# Appendix E Reproductive Tissue Evaluations and Estrous Cycle Characterization

Table E-1 Summary of Reproductive Tissue Evaluations for Male Rats in the Three-month Inhalation Study of Triethylamine^a^

| Chamber Control | | 50 ppm | 100 ppm | 200 ppm
n | 10 | | 10 | 10 | 10
Weights (g)
Necropsy body wt | 347 ± 7 | | 352 ± 8 | 338 ± 4 | 300 ± 5**
L. Cauda epididymis | 0.1820 ± 0.0037 | | 0.1908 ± 0.0053 | 0.1850 ± 0.0029 | 0.1734 ± 0.0045
L. Epididymis | 0.4871 ± 0.0079 | | 0.4915 ± 0.0078 | 0.4913 ± 0.0053 | 0.4684 ± 0.0060
L. Testis | 1.4762 ± 0.0205 | | 1.4897 ± 0.0140 | 1.4572 ± 0.0206 | 1.4254 ± 0.0163
Spermatid measurements
Spermatid heads (10^3^/mg testis) | 126.3 ± 3.1 | | 134.0 ± 2.3 | 138.8 ± 4.4** | 139.2 ± 3.4*
Spermatid heads (10^6^/testis) | 172.6 ± 4.2 | | 183.0 ± 3.9 | 185.9 ± 5.0 | 181.0 ± 4.5
Epididymal spermatozoal measurements
Sperm motility (%) | 91.81 ± 0.82 | | 88.63 ± 0.83* | 87.75 ± 0.85** | 86.26 ± 1.45**
Sperm (10^3^/mg cauda epididymis) | 700.4 ± 38.9 | | 641.5 ± 34.9 | 631.6 ± 19.7 | 664.3 ± 30.3
Sperm (10^6^/cauda epididymis) | 126.7 ± 5.5 | | 121.4 ± 5.3 | 116.4 ± 2.3 | 115.0 ± 5.7

* Significantly different (P ≤ 0.05) from the chamber control group by Shirley’s test (motility and spermatid heads/mg testis measurements).

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ test (body weights) or Shirley’s test (motility and spermatid heads/mg testis measurements).

^a^ Data are presented as mean ± standard error. Differences from the chamber control group are not significant by Dunnett’s test (tissue weights) or Dunn’s test (spermatid heads/testis, sperm/mg cauda epididymis, and sperm/cauda epididymis measurements).

Table E-2 Estrous Cycle Characterization for Female Rats in theThree-month Inhalation Study of Triethylamine^a^

| Chamber Control | 50 ppm | 100 ppm | 200 ppm
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 209 ± 4 | 207 ± 5 | 198 ± 5 | 181 ± 3**
Proportion of regular cycling females^b^ | 10/10 | 10/10 | 9/10 | 9/10
Estrous cycle length (days) | 4.95 ± 0.05 | 5.00 ± 0.00 | 4.78 ± 0.15^c^ | 4.70 ± 0.31
Estrous stages (% of cycle)
Diestrus | 55.0 | 57.5 | 54.2 | 50.0
Proestrus | 19.2 | 17.5 | 15.0 | 14.2
Estrus | 21.7 | 20.0 | 20.8 | 25.0
Metestrus | 3.3 | 5.0 | 10.0 | 10.8
Uncertain diagnosis | 0.8 | 0.0 | 0.0 | 0.0

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ test.

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the chamber control group are not significant by Dunn’s test (estrous cycle length). Evidence shows that females exposed to 200 ppm differ significantly (Wilk’s Criterion, P ≤ 0.05) from the chamber control females in the relative length of time spent in the estrous stages. Females exposed to 200 ppm spent more time in metestrus than chamber control females.

^b^ Number of females with a regular cycle/number of females cycling.

^c^ Estrous cycle was longer than 12 days or unclear in 1 of 10 animals.

Table E-3 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Rats Administered Triethylamine by Inhalation for Three Months

Stage | Comparison | P Value | Trend^a^
Overall tests | Overall | 0.785
Overall tests | 50 ppm vs. chamber controls | 0.811 | –
Overall tests | 100 ppm vs. chamber controls | 0.392 | N
Overall tests | 200 ppm vs. chamber controls | 0.639 | N
Extended estrus | Overall | 0.404
Extended estrus | 50 ppm vs. chamber controls | 0.353 | –
Extended estrus | 100 ppm vs. chamber controls | 0.604 | –
Extended estrus | 200 ppm vs. chamber controls | 0.214 | –
Extended diestrus | Overall | 0.407
Extended diestrus | 50 ppm vs. chamber controls | 0.917 | N
Extended diestrus | 100 ppm vs. chamber controls | 0.286 | N
Extended diestrus | 200 ppm vs. chamber controls | 0.176 | N
Extended metestrus | Overall | 1
Extended metestrus | 50 ppm vs. chamber controls | 1 | –
Extended metestrus | 100 ppm vs. chamber controls | 1 | –
Extended metestrus | 200 ppm vs. chamber controls | 1 | –
Extended proestrus | Overall | 1
Extended proestrus | 50 ppm vs. chamber controls | 1 | –
Extended proestrus | 100 ppm vs. chamber controls | 1 | –
Extended proestrus | 200 ppm vs. chamber controls | 1 | –
Skipped estrus | Overall | 1
Skipped estrus | 50 ppm vs. chamber controls | 1 | –
Skipped estrus | 100 ppm vs. chamber controls | 1 | –
Skipped estrus | 200 ppm vs. chamber controls | 1 | –
Skipped diestrus | Overall | 1
Skipped diestrus | 50 ppm vs. chamber controls | 1 | –
Skipped diestrus | 100 ppm vs. chamber controls | 1 | –
Skipped diestrus | 200 ppm vs. chamber controls | 1 | –

^a^ N means that the treated group had a lower probability of transitioning to the relevant abnormal state (extended estrus, extended diestrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the chamber control group.

Table E-4 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Inhalation Study of Triethylamine^a^

| Chamber Control | 50 ppm | 100 ppm | 200 ppm
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 37.6 ± 0.8 | 38.6 ± 0.5 | 38.3 ± 0.6 | 31.9 ± 0.6**
L. Cauda epididymis | 0.0193 ± 0.0006 | 0.0162 ± 0.0008** | 0.0176 ± 0.0008 | 0.0173 ± 0.0005
L. Epididymis | 0.0544 ± 0.0012 | 0.0532 ± 0.0006 | 0.0540 ± 0.0013 | 0.0487 ± 0.0010**
L. Testis | 0.1135 ± 0.0013 | 0.1108 ± 0.0023 | 0.1099 ± 0.0027 | 0.1074 ± 0.0015
Spermatid measurements
Spermatid heads (10^3^/mg testis) | 185.2 ± 4.9 | 196.6 ± 6.0 | 188.4 ± 7.1 | 200.4 ± 6.0
Spermatid heads (10^6^/testis) | 19.42 ± 0.47 | 20.47 ± 0.76 | 19.29 ± 0.63 | 19.74 ± 0.49
Epididymal spermatozoal measurements
Sperm motility (%) | 88.24 ± 1.04 | 85.47 ± 0.84 | 85.52 ± 0.51 | 86.50 ± 0.91
Sperm (10^3^/mg cauda epididymis) | 1,058 ± 41 | 1,007 ± 52 | 1,007 ± 70 | 1,023 ± 70
Sperm (10^6^/cauda epididymis) | 20.35 ± 0.59 | 16.03 ± 0.48** | 17.39 ± 0.78 | 17.59 ± 1.10

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ test (body and left epididymal weights), Dunnett’s test (left cauda epididymis weights), or Dunn’s test (sperm /cauda epididymis measurements).

^a^ Data are presented as mean ± standard error. Differences from the chamber control group are not significant by Dunnett’s test (left testis weights) or Dunn’s test (spermatid measurements, motility, and sperm /mg cauda epididymis measurements).

Table E-5 Estrous Cycle Characterization for Female Mice in the Three-month Inhalation Study of Triethylamine^a^

| Chamber Control | 50 ppm | 100 ppm | 200 ppm
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 32.8 ± 0.8 | 33.7 ± 0.5 | 33.0 ± 0.4 | 29.3 ± 0.5**
Proportion of regular cycling females^b^ | 10/10 | 7/10 | 9/10 | 6/10*
Estrous cycle length (days) | 4.05 ± 0.05 | 4.20 ± 0.11 | 4.00 ± 0.00^c^ | 4.20 ± 0.19
Estrous stages (% of cycle)
Diestrus | 26.7 | 24.2 | 30.0 | 29.2
Proestrus | 0.0 | 0.0 | 0.0 | 0.0
Estrus | 48.3 | 51.7 | 46.7 | 47.5
Metestrus | 25.0 | 24.2 | 23.3 | 23.3

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s test (proportion of regular cycling females).

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ test (body weights).

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the chamber control group are not significant by Dunn’s test (estrous cycle length). By multivariate analysis of variance, exposed females do not differ significantly from the chamber control females in the relative length of time spent in the estrous stages.

^b^ Number of females with a regular cycle/number of females cycling.

^c^ Estrous cycle was longer than 12 days or unclear in 1 of 10 animals.

Table E-6 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Mice Administered Triethylamine by Inhalation for Three Months

Stage | Comparison | P Value | Trend^a^
Overall tests | Overall | 0.232
Overall tests | 50 ppm vs. chamber controls | 0.207 | –
Overall tests | 100 ppm vs. chamber controls | 0.167 | –
Overall tests | 200 ppm vs. chamber controls | 0.508 | –
Extended estrus | Overall | 0.211
Extended estrus | 50 ppm vs. chamber controls | 0.207 | –
Extended estrus | 100 ppm vs. chamber controls | 1 | –
Extended estrus | 200 ppm vs. chamber controls | 0.073 | –
Extended diestrus | Overall | 0.597
Extended diestrus | 50 ppm vs. chamber controls | 1 | –
Extended diestrus | 100 ppm vs. chamber controls | 0.167 | –
Extended diestrus | 200 ppm vs. chamber controls | 0.604 | –
Extended metestrus | Overall | 1
Extended metestrus | 50 ppm vs. chamber controls | 1 | –
Extended metestrus | 100 ppm vs. chamber controls | 1 | –
Extended metestrus | 200 ppm vs. chamber controls | 1 | –
Extended proestrus | Overall | 1
Extended proestrus | 50 ppm vs. chamber controls | 1 | –
Extended proestrus | 100 ppm vs. chamber controls | 1 | –
Extended proestrus | 200 ppm vs. chamber controls | 1 | –
Skipped estrus | Overall | 1
Skipped estrus | 50 ppm vs. chamber controls | 1 | –
Skipped estrus | 100 ppm vs. chamber controls | 1 | –
Skipped estrus | 200 ppm vs. chamber controls | 1 | –
Skipped diestrus | Overall | 1
Skipped diestrus | 50 ppm vs. chamber controls | 1 | –
Skipped diestrus | 100 ppm vs. chamber controls | 1 | –
Skipped diestrus | 200 ppm vs. chamber controls | 1 | –

^a^ N means that the treated group had a lower probability of transitioning to the relevant abnormal state (extended estrus, extended diestrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the chamber control group.

Figure E-1

Vaginal Cytology Plots for Female Rats in the Three-month Inhalation Study of Triethylamine

I = insufficient number of cells to determine state, D = diestrus, P = proestrus, E = estrus, M = metestrus.

Figure E-2

Vaginal Cytology Plots for Female Mice in the Three-month Inhalation Study of Triethylamine

D = diestrus, E = estrus, M = metestrus.