# Appendix D Organ Weights and Organ-Weight-to-Body-Weight Ratios

Table D-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Two-week Inhalation Study of Triethylamine^a^

| Chamber Control | 100 ppm | 200 ppm | 400 ppm | 800 ppm | 1,000 ppm
n | 5 | 5 | 5 | 5 | 0^b^ | 0^b^
Male
Necropsy body wt | 170 ± 4 | 159 ± 4* | 152 ± 3** | 120 ± 3** | – | –
Heart
Absolute | 0.642 ± 0.023 | 0.564 ± 0.008** | 0.572 ± 0.019* | 0.510 ± 0.018** | – | –
Relative | 3.784 ± 0.133 | 3.550 ± 0.059 | 3.775 ± 0.089 | 4.260 ± 0.099** | – | –
R. Kidney
Absolute | 0.682 ± 0.011 | 0.640 ± 0.014 | 0.654 ± 0.015 | 0.542 ± 0.017** | – | –
Relative | 4.022 ± 0.081 | 4.026 ± 0.061 | 4.321 ± 0.106* | 4.531 ± 0.104** | – | –
Liver
Absolute | 7.750 ± 0.213 | 6.986 ± 0.131* | 6.898 ± 0.281* | 5.414 ± 0.174** | – | –
Relative | 45.626 ± 0.268 | 43.986 ± 1.011 | 45.565 ± 1.817 | 45.215 ± 0.460 | – | –
Lung
Absolute | 1.252 ± 0.114 | 1.498 ± 0.135 | 1.416 ± 0.132 | 1.006 ± 0.072 | – | –
Relative | 7.346 ± 0.544 | 9.414 ± 0.801 | 9.324 ± 0.766 | 8.403 ± 0.552 | – | –
R. Testis
Absolute | 1.090 ± 0.018 | 1.049 ± 0.039 | 1.019 ± 0.018 | 0.630 ± 0.043** | – | –
Relative | 6.427 ± 0.105 | 6.591 ± 0.144 | 6.730 ± 0.068 | 5.252 ± 0.266** | – | –
Thymus
Absolute | 0.447 ± 0.023 | 0.447 ± 0.012 | 0.403 ± 0.018 | 0.184 ± 0.012** | – | –
Relative | 2.626 ± 0.072 | 2.815 ± 0.089 | 2.663 ± 0.112 | 1.536 ± 0.067** | – | –
Female
Necropsy body wt | 128 ± 2 | 125 ± 2 | 117 ± 3** | 103 ± 3** | – | –
Heart
Absolute | 0.482 ± 0.004 | 0.478 ± 0.023 | 0.466 ± 0.006 | 0.468 ± 0.007 | – | –
Relative | 3.764 ± 0.047 | 3.814 ± 0.145 | 3.982 ± 0.069 | 4.548 ± 0.079** | – | –
R. Kidney
Absolute | 0.516 ± 0.014 | 0.570 ± 0.012* | 0.550 ± 0.009 | 0.556 ± 0.014 | – | –
Relative | 4.029 ± 0.108 | 4.555 ± 0.093** | 4.702 ± 0.110** | 5.404 ± 0.153** | – | –
Liver
Absolute | 5.298 ± 0.083 | 5.284 ± 0.199 | 4.940 ± 0.104 | 5.120 ± 0.093 | – | –
Relative | 41.356 ± 0.387 | 42.196 ± 1.335 | 42.185 ± 0.576 | 49.724 ± 0.532** | – | –
Lung
Absolute | 0.866 ± 0.059 | 0.972 ± 0.048 | 1.034 ± 0.081 | 1.036 ± 0.109 | – | –
Relative | 6.753 ± 0.414 | 7.752 ± 0.295 | 8.880 ± 0.843* | 9.986 ± 0.858** | – | –
Thymus
Absolute | 0.381 ± 0.014 | 0.388 ± 0.028 | 0.351 ± 0.019 | 0.174 ± 0.015** | – | –
Relative | 2.972 ± 0.114 | 3.093 ± 0.184 | 2.990 ± 0.128 | 1.684 ± 0.133** | – | –

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

^b^ No data were available for the 800 and 1,000 ppm groups due to 100% mortality.

Table D-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Inhalation Study of Triethylamine^a^

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm | 200 ppm
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 347 ± 7 | 360 ± 8 | 343 ± 9 | 352 ± 8 | 338 ± 4 | 300 ± 5**
Heart
Absolute | 0.955 ± 0.021 | 0.973 ± 0.022 | 0.957 ± 0.021 | 0.955 ± 0.022 | 0.943 ± 0.010 | 0.860 ± 0.013**
Relative | 2.755 ± 0.027 | 2.707 ± 0.029 | 2.800 ± 0.046 | 2.716 ± 0.033 | 2.792 ± 0.022 | 2.868 ± 0.024*
R. Kidney
Absolute | 1.041 ± 0.020 | 1.085 ± 0.024 | 1.046 ± 0.034 | 1.094 ± 0.022 | 1.038 ± 0.013 | 0.976 ± 0.016
Relative | 3.006 ± 0.042 | 3.017 ± 0.019 | 3.052 ± 0.039 | 3.113 ± 0.026 | 3.073 ± 0.033 | 3.256 ± 0.041**
Liver
Absolute | 11.36 ± 0.29 | 12.14 ± 0.52 | 11.27 ± 0.45 | 11.71 ± 0.39 | 11.15 ± 0.20 | 10.17 ± 0.24*
Relative | 32.755 ± 0.263 | 33.625 ± 0.754 | 32.816 ± 0.469 | 33.245 ± 0.545 | 32.973 ± 0.348 | 33.875 ± 0.426
Lung
Absolute | 1.874 ± 0.094 | 1.693 ± 0.056 | 1.697 ± 0.089 | 1.714 ± 0.081 | 1.692 ± 0.038 | 1.500 ± 0.049**
Relative | 5.394 ± 0.223 | 4.707 ± 0.113** | 4.934 ± 0.156 | 4.857 ± 0.142 | 5.009 ± 0.106 | 4.993 ± 0.107
R. Testis
Absolute | 1.429 ± 0.012 | 1.432 ± 0.028 | 1.445 ± 0.031 | 1.453 ± 0.012 | 1.481 ± 0.058 | 1.370 ± 0.018
Relative | 4.135 ± 0.085 | 3.987 ± 0.059 | 4.229 ± 0.067 | 4.146 ± 0.081 | 4.386 ± 0.174 | 4.573 ± 0.064**
Thymus
Absolute | 0.325 ± 0.015 | 0.298 ± 0.010 | 0.319 ± 0.011 | 0.304 ± 0.018 | 0.318 ± 0.013 | 0.257 ± 0.013**
Relative | 0.937 ± 0.035 | 0.830 ± 0.030 | 0.932 ± 0.028 | 0.865 ± 0.047 | 0.941 ± 0.034 | 0.856 ± 0.042
Female
Necropsy body wt | 209 ± 4 | 211 ± 4 | 204 ± 3 | 207 ± 5 | 198 ± 5 | 181 ± 3**
Heart
Absolute | 0.646 ± 0.017 | 0.650 ± 0.011 | 0.630 ± 0.007 | 0.639 ± 0.013 | 0.623 ± 0.015 | 0.584 ± 0.007**
Relative | 3.096 ± 0.053 | 3.096 ± 0.074 | 3.088 ± 0.049 | 3.088 ± 0.039 | 3.164 ± 0.100 | 3.223 ± 0.045
R. Kidney
Absolute | 0.689 ± 0.016 | 0.700 ± 0.010 | 0.692 ± 0.008 | 0.696 ± 0.012 | 0.684 ± 0.014 | 0.656 ± 0.007
Relative | 3.305 ± 0.067 | 3.327 ± 0.026 | 3.390 ± 0.044 | 3.368 ± 0.063 | 3.465 ± 0.060* | 3.620 ± 0.042**
Liver
Absolute | 6.460 ± 0.179 | 6.664 ± 0.179 | 6.464 ± 0.121 | 6.441 ± 0.193 | 6.245 ± 0.219 | 5.768 ± 0.064**
Relative | 30.940 ± 0.514 | 31.638 ± 0.523 | 31.657 ± 0.535 | 31.078 ± 0.524 | 31.529 ± 0.634 | 31.849 ± 0.556
Lung
Absolute | 1.160 ± 0.025 | 1.218 ± 0.027 | 1.168 ± 0.024 | 1.251 ± 0.042 | 1.212 ± 0.028 | 1.132 ± 0.017
Relative | 5.560 ± 0.066 | 5.790 ± 0.109 | 5.732 ± 0.165 | 6.042 ± 0.157* | 6.156 ± 0.198** | 6.257 ± 0.157**
Thymus
Absolute | 0.284 ± 0.015 | 0.295 ± 0.016 | 0.285 ± 0.010 | 0.292 ± 0.008 | 0.264 ± 0.012 | 0.242 ± 0.011*
Relative | 1.358 ± 0.062 | 1.400 ± 0.066 | 1.396 ± 0.057 | 1.414 ± 0.050 | 1.341 ± 0.063 | 1.335 ± 0.065

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ or Dunnett’s test.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table D-3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Two-week Inhalation Study of Triethylamine^a^

| Chamber Control | 100 ppm | 200 ppm | 400 ppm | 800 ppm | 1,000 ppm
n | 5 | 5 | 5 | 5 | 0^b^ | 0^b^
Male
Necropsy body wt | 26.2 ± 0.6 | 25.6 ± 0.6 | 24.7 ± 0.5 | 19.4 ± 0.6** | – | –
Heart
Absolute | 0.124 ± 0.005 | 0.116 ± 0.004 | 0.116 ± 0.002 | 0.098 ± 0.002** | – | –
Relative | 4.724 ± 0.147 | 4.534 ± 0.107 | 4.696 ± 0.093 | 5.068 ± 0.063 | – | –
R. Kidney
Absolute | 0.214 ± 0.002 | 0.230 ± 0.010 | 0.228 ± 0.007 | 0.170 ± 0.008** | – | –
Relative | 8.166 ± 0.129 | 8.980 ± 0.292 | 9.235 ± 0.322* | 8.766 ± 0.193 | – | –
Liver
Absolute | 1.348 ± 0.044 | 1.276 ± 0.055 | 1.182 ± 0.040* | 0.930 ± 0.046** | – | –
Relative | 51.364 ± 1.117 | 49.800 ± 1.052 | 47.764 ± 0.748 | 47.916 ± 1.131 | – | –
Lung
Absolute | 0.180 ± 0.007 | 0.180 ± 0.010 | 0.182 ± 0.006 | 0.174 ± 0.010 | – | –
Relative | 6.863 ± 0.236 | 7.026 ± 0.280 | 7.367 ± 0.217 | 8.961 ± 0.277** | – | –
R. Testis
Absolute | 0.102 ± 0.003 | 0.104 ± 0.002 | 0.103 ± 0.003 | 0.096 ± 0.002 | – | –
Relative | 3.873 ± 0.067 | 4.072 ± 0.099 | 4.189 ± 0.125* | 4.954 ± 0.065** | – | –
Thymus
Absolute | 0.058 ± 0.005 | 0.056 ± 0.001 | 0.043 ± 0.002** | 0.015 ± 0.003** | – | –
Relative | 2.219 ± 0.152 | 2.175 ± 0.022 | 1.740 ± 0.080** | 0.785 ± 0.115** | – | –
Female
Necropsy body wt | 22.7 ± 0.4 | 22.9 ± 0.4 | 21.8 ± 0.5 | 17.1 ± 0.3** | – | –
Heart
Absolute | 0.116 ± 0.002 | 0.128 ± 0.013 | 0.110 ± 0.005 | 0.086 ± 0.004* | – | –
Relative | 5.102 ± 0.067 | 5.582 ± 0.553 | 5.031 ± 0.153 | 5.021 ± 0.149 | – | –
R. Kidney
Absolute | 0.172 ± 0.007 | 0.174 ± 0.007 | 0.166 ± 0.007 | 0.146 ± 0.002** | – | –
Relative | 7.555 ± 0.191 | 7.603 ± 0.342 | 7.599 ± 0.190 | 8.544 ± 0.136* | – | –
Liver
Absolute | 1.218 ± 0.041 | 1.170 ± 0.020 | 1.148 ± 0.044 | 0.836 ± 0.015** | – | –
Relative | 53.509 ± 0.951 | 51.071 ± 0.773 | 52.546 ± 1.013 | 48.903 ± 0.465** | – | –
Lung
Absolute | 0.186 ± 0.010 | 0.210 ± 0.024 | 0.190 ± 0.009 | 0.190 ± 0.013 | – | –
Relative | 8.186 ± 0.448 | 9.138 ± 0.965 | 8.690 ± 0.231 | 11.130 ± 0.815** | – | –
Thymus
Absolute | 0.081 ± 0.008 | 0.075 ± 0.002 | 0.065 ± 0.010 | 0.017 ± 0.002** | – | –
Relative | 3.563 ± 0.311 | 3.256 ± 0.092 | 2.954 ± 0.420 | 0.966 ± 0.101** | – | –

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

^b^ No data were available for the 800 and 1,000 ppm groups due to 100% mortality.

Table D-4 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Inhalation Study of Triethylamine^a^

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm | 200 ppm
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 37.6 ± 0.8 | 38.3 ± 0.9 | 37.6 ± 0.7 | 38.6 ± 0.5 | 38.3 ± 0.6 | 31.9 ± 0.6**
Heart
Absolute | 0.162 ± 0.003 | 0.169 ± 0.003 | 0.161 ± 0.002 | 0.169 ± 0.004 | 0.162 ± 0.003 | 0.145 ± 0.003**
Relative | 4.314 ± 0.092 | 4.421 ± 0.087 | 4.299 ± 0.091 | 4.386 ± 0.105 | 4.238 ± 0.084 | 4.550 ± 0.102
R. Kidney
Absolute | 0.309 ± 0.008 | 0.310 ± 0.006 | 0.315 ± 0.005 | 0.327 ± 0.010 | 0.315 ± 0.007 | 0.278 ± 0.006*
Relative | 8.232 ± 0.226 | 8.111 ± 0.171 | 8.400 ± 0.118 | 8.474 ± 0.213 | 8.234 ± 0.165 | 8.718 ± 0.177
Liver
Absolute | 1.644 ± 0.046 | 1.648 ± 0.041 | 1.582 ± 0.032 | 1.615 ± 0.030 | 1.599 ± 0.020 | 1.322 ± 0.038**
Relative | 43.681 ± 0.759 | 43.040 ± 0.671 | 42.199 ± 0.848 | 41.865 ± 0.443 | 41.832 ± 0.648 | 41.463 ± 1.135
Lung
Absolute | 0.227 ± 0.005 | 0.240 ± 0.007 | 0.230 ± 0.003 | 0.231 ± 0.003 | 0.233 ± 0.004 | 0.216 ± 0.006
Relative | 6.039 ± 0.105 | 6.277 ± 0.193 | 6.145 ± 0.145 | 5.997 ± 0.096 | 6.096 ± 0.125 | 6.768 ± 0.130**
R. Testis
Absolute | 0.123 ± 0.002 | 0.117 ± 0.003 | 0.120 ± 0.002 | 0.131 ± 0.005 | 0.119 ± 0.003 | 0.120 ± 0.002
Relative | 3.272 ± 0.095 | 3.068 ± 0.102 | 3.211 ± 0.083 | 3.397 ± 0.138 | 3.114 ± 0.065 | 3.783 ± 0.117**
Thymus
Absolute | 0.052 ± 0.003 | 0.048 ± 0.002 | 0.049 ± 0.002 | 0.052 ± 0.003 | 0.049 ± 0.002 | 0.038 ± 0.002**
Relative | 1.395 ± 0.097 | 1.256 ± 0.069 | 1.317 ± 0.063 | 1.349 ± 0.066 | 1.267 ± 0.055 | 1.182 ± 0.050
Female
Necropsy body wt | 32.8 ± 0.8 | 32.8 ± 0.9 | 31.4 ± 0.8 | 33.7 ± 0.5 | 33.0 ± 0.4 | 29.3 ± 0.5**
Heart
Absolute | 0.140 ± 0.003 | 0.152 ± 0.003* | 0.148 ± 0.003 | 0.148 ± 0.002 | 0.156 ± 0.004** | 0.140 ± 0.003
Relative | 4.279 ± 0.099 | 4.644 ± 0.074 | 4.731 ± 0.139* | 4.397 ± 0.091 | 4.733 ± 0.135* | 4.782 ± 0.077**
R. Kidney
Absolute | 0.210 ± 0.006 | 0.217 ± 0.003 | 0.213 ± 0.005 | 0.214 ± 0.004 | 0.216 ± 0.006 | 0.200 ± 0.005
Relative | 6.409 ± 0.165 | 6.661 ± 0.220 | 6.794 ± 0.130 | 6.357 ± 0.141 | 6.537 ± 0.125 | 6.826 ± 0.087
Liver
Absolute | 1.531 ± 0.039 | 1.512 ± 0.056 | 1.489 ± 0.043 | 1.499 ± 0.042 | 1.533 ± 0.022 | 1.312 ± 0.031**
Relative | 46.716 ± 0.855 | 46.059 ± 0.914 | 47.406 ± 0.683 | 44.465 ± 1.056 | 46.451 ± 0.618 | 44.794 ± 0.557
Lung
Absolute | 0.229 ± 0.004 | 0.245 ± 0.012 | 0.225 ± 0.006 | 0.234 ± 0.007 | 0.248 ± 0.010 | 0.229 ± 0.007
Relative | 7.011 ± 0.204 | 7.504 ± 0.384 | 7.204 ± 0.268 | 6.956 ± 0.221 | 7.519 ± 0.327 | 7.832 ± 0.250
Thymus
Absolute | 0.055 ± 0.003 | 0.059 ± 0.003 | 0.064 ± 0.012 | 0.057 ± 0.002 | 0.054 ± 0.003 | 0.048 ± 0.002
Relative | 1.667 ± 0.099 | 1.809 ± 0.117 | 2.021 ± 0.360 | 1.686 ± 0.074 | 1.646 ± 0.087 | 1.654 ± 0.048

* Significantly different (P ≤ 0.05) from the chamber control group by Dunnett’s test.

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ or Dunnett’s test.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).