# Appendix C Clinical Pathology Results

Table C-1 Clinical Pathology Data for Rats in the Three-month Inhalation Study of Triethylamine^a^

| Chamber Control | | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm | | 200 ppm
Male
Hematology
n
Day 3 | 10 | | 10 | 10 | 10 | 10 | | 10
Day 23 | 10 | | 10 | 10 | 10 | 9 | | 10
Week 14 | 9 | | 10 | 9 | 10 | 10 | | 10
Hematocrit (spun) (%)
Day 3 | 47.0 ± 0.4 | | 46.1 ± 0.7 | 45.8 ± 0.5 | 45.0 ± 0.4* | 46.6 ± 0.7 | | 47.4 ± 0.4
Day 23 | 47.3 ± 0.3 | | 47.7 ± 0.4 | 47.2 ± 0.5 | 47.6 ± 0.3 | 47.8 ± 0.4 | | 48.3 ± 0.5
Week 14 | 49.0 ± 0.5 | | 48.0 ± 0.3 | 48.8 ± 0.5 | 49.1 ± 0.5 | 49.0 ± 0.4 | | 49.0 ± 0.3
Hematocrit (mL/dL)
Day 3 | 45.2 ± 0.5 | | 44.5 ± 0.7 | 44.1 ± 0.6 | 43.6 ± 0.4 | 45.0 ± 0.6 | | 45.9 ± 0.4
Day 23 | 46.2 ± 0.4 | | 46.8 ± 0.4 | 46.4 ± 0.5 | 46.6 ± 0.2 | 47.0 ± 0.5 | | 47.4 ± 0.5
Week 14 | 48.8 ± 0.5 | | 47.4 ± 0.3 | 48.7 ± 0.3 | 49.0 ± 0.4 | 48.6 ± 0.4 | | 48.7 ± 0.3
Hemoglobin (g/dL)
Day 3 | 14.1 ± 0.2 | | 14.0 ± 0.2 | 13.9 ± 0.2 | 13.7 ± 0.2 | 14.3 ± 0.2 | | 14.8 ± 0.2
Day 23 | 15.1 ± 0.1 | | 15.3 ± 0.1 | 15.3 ± 0.2 | 15.1 ± 0.1 | 15.4 ± 0.2 | | 15.4 ± 0.1
Week 14 | 15.8 ± 0.1 | | 15.5 ± 0.1 | 15.8 ± 0.1 | 16.0 ± 0.1 | 15.8 ± 0.1 | | 15.9 ± 0.1
Erythrocytes (10^6^/μL)
Day 3 | 7.23 ± 0.10 | | 7.14 ± 0.14 | 7.06 ± 0.14 | 7.04 ± 0.08 | 7.32 ± 0.11 | | 7.65 ± 0.11
Day 23 | 7.90 ± 0.06 | | 7.98 ± 0.10 | 7.89 ± 0.14 | 7.93 ± 0.07 | 8.13 ± 0.11 | | 8.20 ± 0.09
Week 14 | 9.24 ± 0.08 | | 9.03 ± 0.06 | 9.19 ± 0.06 | 9.30 ± 0.07 | 9.19 ± 0.07 | | 9.09 ± 0.11
Reticulocytes (10^3^/μL)
Day 3 | 343.5 ± 15.4 | | 327.3 ± 27.4 | 305.9 ± 19.8 | 340.4 ± 13.1 | 281.7 ± 20.1 | | 284.2 ± 19.8
Day 23 | 240.5 ± 9.4 | | 223.4 ± 19.0 | 203.9 ± 10.0 | 207.2 ± 15.5 | 221.9 ± 15.8 | | 263.5 ± 9.3
Week 14 | 203.2 ± 10.8 | | 220.4 ± 11.5 | 201.1 ± 10.4 | 237.5 ± 12.2 | 211.1 ± 14.8 | | 195.3 ± 12.7
Nucleated erythrocytes/100 leukocytes
Day 3 | 1.50 ± 0.52 | | 1.40 ± 0.34 | 1.60 ± 0.64 | 1.00 ± 0.39 | 0.90 ± 0.23 | | 0.40 ± 0.22
Day 23 | 0.10 ± 0.10 | | 0.10 ± 0.10 | 0.30 ± 0.15 | 0.20 ± 0.13 | 0.33 ± 0.17 | | 0.30 ± 0.15
Week 14 | 0.11 ± 0.11 | | 0.00 ± 0.00 | 0.33 ± 0.24 | 0.00 ± 0.00 | 0.20 ± 0.13 | | 0.00 ± 0.00
Mean cell volume (fL)
Day 3 | 62.5 ± 0.3 | | 62.4 ± 0.4 | 62.6 ± 0.6 | 61.9 ± 0.4 | 61.4 ± 0.4 | | 60.0 ± 0.5**
Day 23 | 58.5 ± 0.3 | | 58.7 ± 0.4 | 58.9 ± 0.5 | 58.8 ± 0.3 | 57.7 ± 0.4 | | 57.8 ± 0.4
Week 14 | 52.8 ± 0.1 | | 52.5 ± 0.2 | 53.0 ± 0.2 | 52.7 ± 0.1 | 52.8 ± 0.2 | | 53.0 ± 0.2
Mean cell hemoglobin (pg)
Day 3 | 19.5 ± 0.1 | | 19.7 ± 0.1 | 19.7 ± 0.1 | 19.5 ± 0.1 | 19.6 ± 0.1 | | 19.4 ± 0.1
Day 23 | 19.1 ± 0.0 | | 19.2 ± 0.1 | 19.3 ± 0.1 | 19.1 ± 0.1 | 18.9 ± 0.1 | | 18.7 ± 0.1*
Week 14 | 17.1 ± 0.0 | | 17.2 ± 0.1 | 17.2 ± 0.1 | 17.1 ± 0.0 | 17.2 ± 0.1 | | 17.3 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 3 | 31.2 ± 0.3 | | 31.5 ± 0.2 | 31.4 ± 0.2 | 31.5 ± 0.2 | 31.8 ± 0.1 | | 32.3 ± 0.2**
Day 23 | 32.6 ± 0.1 | | 32.7 ± 0.2 | 32.8 ± 0.2 | 32.5 ± 0.1 | 32.7 ± 0.1 | | 32.4 ± 0.2
Week 14 | 32.4 ± 0.1 | | 32.8 ± 0.1 | 32.5 ± 0.1 | 32.5 ± 0.1 | 32.5 ± 0.2 | | 32.6 ± 0.1
Platelets (10^3^/μL)
Day 3 | 859.9 ± 19.2 | | 846.8 ± 13.4 | 864.2 ± 21.0 | 851.7 ± 13.1 | 824.6 ± 20.6 | | 862.2 ± 24.5
Day 23 | 804.0 ± 17.5 | | 746.6 ± 24.0 | 766.0 ± 18.5 | 784.7 ± 15.0 | 761.2 ± 19.8 | | 791.5 ± 13.5
Week 14 | 656.7 ± 21.1 | | 666.5 ± 12.6 | 660.8 ± 6.6 | 676.6 ± 10.0 | 653.6 ± 14.3 | | 614.3 ± 13.1
Leukocytes (10^3^/μL)
Day 3 | 12.20 ± 0.71 | | 11.68 ± 0.62 | 9.82 ± 0.46** | 9.39 ± 0.60** | 8.35 ± 0.33** | | 9.33 ± 0.39**
Day 23 | 7.84 ± 0.34 | | 8.68 ± 0.61 | 8.65 ± 0.37 | 7.46 ± 0.32 | 7.66 ± 0.65 | | 6.86 ± 0.22
Week 14 | 8.08 ± 0.51 | | 8.14 ± 0.28 | 8.33 ± 0.43 | 8.44 ± 0.63 | 9.44 ± 0.54 | | 7.82 ± 0.30
Segmented neutrophils (10^3^/μL)
Day 3 | 1.14 ± 0.07 | | 1.09 ± 0.09 | 0.93 ± 0.03 | 0.87 ± 0.05* | 0.81 ± 0.06** | | 1.07 ± 0.08
Day 23 | 1.10 ± 0.05 | | 1.04 ± 0.03 | 0.96 ± 0.04 | 1.04 ± 0.05 | 1.09 ± 0.06 | | 1.19 ± 0.09
Week 14 | 1.46 ± 0.08 | | 1.49 ± 0.09 | 1.44 ± 0.04 | 1.51 ± 0.09 | 1.51 ± 0.12 | | 1.35 ± 0.07
Lymphocytes (10^3^/μL)
Day 3 | 10.73 ± 0.65 | | 10.36 ± 0.56 | 8.60 ± 0.45** | 8.19 ± 0.56** | 7.32 ± 0.32** | | 8.08 ± 0.35**
Day 23 | 6.59 ± 0.31 | | 7.44 ± 0.61 | 7.48 ± 0.37 | 6.27 ± 0.31 | 6.38 ± 0.67 | | 5.43 ± 0.21*
Week 14 | 6.47 ± 0.50 | | 6.45 ± 0.26 | 6.75 ± 0.45 | 6.74 ± 0.59 | 7.78 ± 0.49 | | 6.31 ± 0.29
Monocytes (10^3^/μL)
Day 3 | 0.20 ± 0.06 | | 0.11 ± 0.02 | 0.21 ± 0.04 | 0.21 ± 0.05 | 0.11 ± 0.03 | | 0.11 ± 0.03
Day 23 | 0.07 ± 0.02 | | 0.11 ± 0.04 | 0.12 ± 0.03 | 0.07 ± 0.02 | 0.09 ± 0.03 | | 0.18 ± 0.05
Week 14 | 0.07 ± 0.02 | | 0.11 ± 0.02 | 0.04 ± 0.02 | 0.10 ± 0.02 | 0.09 ± 0.02 | | 0.09 ± 0.02
Basophils (10^3^/μL)
Day 3 | 0.012 ± 0.002 | | 0.006 ± 0.002 | 0.006 ± 0.002 | 0.006 ± 0.002 | 0.004 ± 0.002 | | 0.015 ± 0.004
Day 23 | 0.006 ± 0.002 | | 0.005 ± 0.002 | 0.010 ± 0.003 | 0.002 ± 0.001 | 0.008 ± 0.003 | | 0.005 ± 0.002
Week 14 | 0.000 ± 0.000 | | 0.003 ± 0.002 | 0.000 ± 0.000 | 0.001 ± 0.001 | 0.000 ± 0.000 | | 0.001 ± 0.001
Eosinophils (10^3^/μL)
Day 3 | 0.12 ± 0.01 | | 0.12 ± 0.01 | 0.08 ± 0.02 | 0.11 ± 0.02 | 0.10 ± 0.03* | | 0.06 ± 0.01**
Day 23 | 0.08 ± 0.01 | | 0.08 ± 0.01 | 0.08 ± 0.01 | 0.08 ± 0.01 | 0.09 ± 0.01 | | 0.06 ± 0.00
Week 14 | 0.07 ± 0.02 | | 0.10 ± 0.02 | 0.10 ± 0.02 | 0.10 ± 0.02 | 0.07 ± 0.02 | | 0.07 ± 0.02
Immature neutrophils (10^3^/μL)
Day 3 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000
Day 23 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000
Week 14 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000
Clinical Chemistry
n
Day 3 | 10 | | 10 | 10 | 10 | 10 | | 10
Day 23 | 10 | | 10 | 10 | 10 | 9 | | 10
Week 14 | 10 | | 10 | 10 | 10 | 10 | | 10
Urea nitrogen (mg/dL)
Day 3 | 10.1 ± 0.3 | | 7.7 ± 0.4** | 8.5 ± 0.5 | 7.1 ± 0.3** | 8.6 ± 0.3 | | 11.3 ± 0.6
Day 23 | 10.5 ± 0.5 | | 10.5 ± 0.4 | 10.1 ± 0.5 | 9.5 ± 0.3 | 9.9 ± 0.5 | | 9.5 ± 0.5
Week 14 | 14.9 ± 0.5 | | 14.2 ± 0.4 | 14.0 ± 0.4 | 14.8 ± 0.4 | 13.7 ± 0.3 | | 13.9 ± 0.5
Creatinine (mg/dL)
Day 3 | 0.50 ± 0.00^b^ | | 0.49 ± 0.01 | 0.49 ± 0.02 | 0.48 ± 0.01 | 0.53 ± 0.02 | | 0.48 ± 0.01
Day 23 | 0.57 ± 0.02 | | 0.57 ± 0.02 | 0.60 ± 0.00 | 0.60 ± 0.02 | 0.60 ± 0.02 | | 0.61 ± 0.01
Week 14 | 0.61 ± 0.02 | | 0.58 ± 0.03 | 0.57 ± 0.03 | 0.58 ± 0.01 | 0.59 ± 0.01 | | 0.58 ± 0.01
Total protein (g/dL)
Day 3 | 6.1 ± 0.1^b^ | | 6.0 ± 0.1 | 6.0 ± 0.1 | 5.9 ± 0.1 | 5.8 ± 0.1 | | 6.1 ± 0.1
Day 23 | 6.3 ± 0.1 | | 6.4 ± 0.1 | 6.2 ± 0.0 | 6.4 ± 0.1 | 6.3 ± 0.1 | | 6.2 ± 0.0
Week 14 | 7.2 ± 0.0 | | 7.1 ± 0.1 | 7.2 ± 0.1 | 7.2 ± 0.0 | 7.0 ± 0.1* | | 6.7 ± 0.1**
Albumin (g/dL)
Day 3 | 4.5 ± 0.0 | | 4.4 ± 0.1 | 4.4 ± 0.1 | 4.4 ± 0.0 | 4.4 ± 0.0 | | 4.5 ± 0.0
Day 23 | 4.5 ± 0.0 | | 4.5 ± 0.0 | 4.4 ± 0.0 | 4.4 ± 0.0 | 4.4 ± 0.0 | | 4.4 ± 0.0
Week 14 | 4.7 ± 0.0 | | 4.7 ± 0.0 | 4.7 ± 0.0 | 4.7 ± 0.0 | 4.6 ± 0.0** | | 4.5 ± 0.0**
Globulin (g/dL)
Day 3 | 1.6 ± 0.0^b^ | | 1.6 ± 0.1 | 1.6 ± 0.0 | 1.5 ± 0.0 | 1.5 ± 0.1 | | 1.7 ± 0.0
Day 23 | 1.9 ± 0.0 | | 1.9 ± 0.0 | 1.8 ± 0.0 | 1.9 ± 0.0 | 1.8 ± 0.0 | | 1.8 ± 0.0
Week 14 | 2.5 ± 0.0 | | 2.5 ± 0.0 | 2.5 ± 0.0 | 2.6 ± 0.0 | 2.5 ± 0.0 | | 2.2 ± 0.0**
A/G ratio
Day 3 | 2.8 ± 0.1^b^ | | 2.8 ± 0.1 | 2.8 ± 0.1 | 3.0 ± 0.1 | 3.4 ± 0.6 | | 2.7 ± 0.1
Day 23 | 2.4 ± 0.0 | | 2.4 ± 0.0 | 2.5 ± 0.0 | 2.3 ± 0.1 | 2.4 ± 0.0 | | 2.5 ± 0.0
Week 14 | 1.9 ± 0.0 | | 1.9 ± 0.0 | 1.9 ± 0.0 | 1.8 ± 0.0 | 1.9 ± 0.0 | | 2.0 ± 0.0*
Alanine aminotransferase (IU/L)
Day 3 | 55 ± 2 | | 54 ± 2 | 55 ± 3 | 50 ± 2 | 49 ± 1* | | 41 ± 1**
Day 23 | 41 ± 1 | | 41 ± 1 | 38 ± 1 | 40 ± 1 | 41 ± 1 | | 39 ± 1
Week 14 | 81 ± 5 | | 81 ± 5 | 77 ± 3 | 75 ± 4 | 69 ± 2* | | 57 ± 3**
Alkaline phosphatase (IU/L)
Day 3 | 678 ± 11 | | 695 ± 15 | 650 ± 14 | 638 ± 11 | 608 ± 10** | | 565 ± 7**
Day 23 | 474 ± 15 | | 446 ± 13 | 424 ± 17 | 450 ± 12 | 449 ± 18 | | 475 ± 9
Week 14 | 254 ± 4 | | 237 ± 5 | 243 ± 8 | 227 ± 5** | 224 ± 6** | | 228 ± 6**
Creatine kinase (IU/L)
Day 3 | 701 ± 163^b^ | | 579 ± 81 | 486 ± 33^b^ | 401 ± 35 | 733 ± 159 | | 446 ± 59
Day 23 | 333 ± 22 | | 396 ± 50 | 369 ± 35 | 327 ± 21 | 427 ± 43 | | 367 ± 38
Week 14 | 237 ± 25 | | 267 ± 22 | 236 ± 27 | 269 ± 34 | 324 ± 89 | | 219 ± 33
Sorbitol dehydrogenase (IU/L)
Day 3 | 14 ± 1 | | 15 ± 1 | 14 ± 1 | 15 ± 1 | 14 ± 1 | | 14 ± 1
Day 23 | 14 ± 0 | | 13 ± 1 | 13 ± 1 | 13 ± 0 | 12 ± 1 | | 12 ± 1
Week 14 | 21 ± 1 | | 20 ± 1 | 21 ± 1 | 19 ± 1 | 18 ± 1 | | 16 ± 1**
Bile salts (µmol/L)
Day 3 | 6.2 ± 0.6 | | 6.7 ± 1.2 | 10.1 ± 2.2 | 5.8 ± 0.6 | 6.8 ± 1.0 | | 6.3 ± 0.9
Day 23 | 4.5 ± 0.3 | | 4.3 ± 0.3 | 4.0 ± 0.1 | 4.2 ± 0.5 | 3.6 ± 0.3 | | 4.5 ± 0.5
Week 14 | 3.9 ± 0.3 | | 3.7 ± 0.3 | 4.1 ± 0.8 | 3.1 ± 0.1** | 3.7 ± 0.7** | | 4.2 ± 1.1*
Female
Hematology
n | 10 | | 10 | 10 | 10 | 10 | | 10
Hematocrit (spun) (%)
Day 3 | 48.0 ± 0.4 | | 47.7 ± 0.5 | 47.5 ± 0.6 | 48.2 ± 0.3 | 48.3 ± 0.5 | | 49.4 ± 0.6
Day 23 | 47.9 ± 0.3 | | 48.6 ± 0.2 | 48.3 ± 0.3 | 48.3 ± 0.3 | 47.8 ± 0.4 | | 49.8 ± 0.5**
Week 14 | 47.3 ± 0.5 | | 48.2 ± 0.4 | 48.0 ± 0.5 | 47.7 ± 0.3 | 48.9 ± 0.6 | | 47.9 ± 0.5
Hematocrit (mL/dL)
Day 3 | 47.1 ± 0.4 | | 46.9 ± 0.5 | 46.5 ± 0.6 | 46.9 ± 0.3 | 47.4 ± 0.5 | | 48.6 ± 0.6
Day 23 | 47.9 ± 0.3 | | 48.4 ± 0.2 | 48.5 ± 0.4 | 48.2 ± 0.3 | 47.5 ± 0.3 | | 49.4 ± 0.4*
Week 14 | 47.2 ± 0.4 | | 48.0 ± 0.4 | 48.1 ± 0.5 | 47.6 ± 0.3 | 49.0 ± 0.5* | | 48.0 ± 0.5
Hemoglobin (g/dL)
Day 3 | 14.8 ± 0.2 | | 14.8 ± 0.2 | 14.7 ± 0.2 | 14.8 ± 0.1 | 14.9 ± 0.1 | | 15.3 ± 0.2
Day 23 | 15.7 ± 0.1 | | 16.1 ± 0.1 | 15.9 ± 0.1 | 15.7 ± 0.1 | 15.6 ± 0.1 | | 16.2 ± 0.2*
Week 14 | 15.6 ± 0.1 | | 15.7 ± 0.1 | 15.8 ± 0.2 | 15.6 ± 0.1 | 16.0 ± 0.2 | | 15.7 ± 0.2
Erythrocytes (10^6^/μL)
Day 3 | 7.64 ± 0.11 | | 7.69 ± 0.09 | 7.64 ± 0.11 | 7.71 ± 0.07 | 7.74 ± 0.09 | | 8.02 ± 0.13
Day 23 | 8.04 ± 0.10 | | 8.33 ± 0.07 | 8.17 ± 0.06 | 8.23 ± 0.06 | 8.07 ± 0.09 | | 8.56 ± 0.09**
Week 14 | 8.45 ± 0.06 | | 8.56 ± 0.08 | 8.56 ± 0.08 | 8.50 ± 0.07 | 8.71 ± 0.07 | | 8.56 ± 0.08
Reticulocytes (10^3^/μL)
Day 3 | 300.6 ± 21.2 | | 287.2 ± 25.2 | 251.1 ± 18.1 | 261.3 ± 21.5 | 254.8 ± 21.2 | | 271.9 ± 19.3
Day 23 | 155.5 ± 5.9 | | 134.2 ± 9.1 | 156.0 ± 12.2 | 151.8 ± 12.6 | 158.6 ± 15.1 | | 132.5 ± 12.0
Week 14 | 139.7 ± 12.2 | | 165.6 ± 11.3 | 178.6 ± 16.0 | 159.8 ± 8.7 | 132.6 ± 8.7 | | 129.4 ± 6.8
Nucleated erythrocytes/100 leukocytes
Day 3 | 0.60 ± 0.27 | | 0.30 ± 0.21 | 0.40 ± 0.16 | 0.50 ± 0.27 | 0.80 ± 0.33 | | 0.90 ± 0.38
Day 23 | 0.00 ± 0.00 | | 0.10 ± 0.10 | 0.00 ± 0.00 | 0.10 ± 0.10 | 0.20 ± 0.13 | | 0.10 ± 0.10
Week 14 | 0.80 ± 0.25 | | 0.90 ± 0.31 | 0.80 ± 0.25 | 0.40 ± 0.16 | 0.50 ± 0.17 | | 0.50 ± 0.22
Mean cell volume (fL)
Day 3 | 61.7 ± 0.4 | | 61.1 ± 0.3 | 60.9 ± 0.5 | 60.9 ± 0.4 | 61.2 ± 0.3 | | 60.6 ± 0.5
Day 23 | 59.6 ± 0.5 | | 58.1 ± 0.3 | 59.4 ± 0.4 | 58.6 ± 0.3 | 58.9 ± 0.4 | | 57.8 ± 0.4*
Week 14 | 55.9 ± 0.2 | | 56.1 ± 0.3 | 56.2 ± 0.2 | 56.1 ± 0.2 | 56.3 ± 0.2 | | 56.1 ± 0.3
Mean cell hemoglobin (pg)
Day 3 | 19.4 ± 0.1 | | 19.2 ± 0.1 | 19.3 ± 0.1 | 19.3 ± 0.1 | 19.3 ± 0.1 | | 19.1 ± 0.1
Day 23 | 19.5 ± 0.1 | | 19.3 ± 0.1 | 19.4 ± 0.1 | 19.1 ± 0.1 | 19.4 ± 0.1 | | 19.0 ± 0.1**
Week 14 | 18.4 ± 0.0 | | 18.4 ± 0.1 | 18.4 ± 0.1 | 18.4 ± 0.1 | 18.4 ± 0.1 | | 18.4 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 3 | 31.5± 0.2 | | 31.5 ± 0.2 | 31.6 ± 0.2 | 31.6 ± 0.2 | 31.6 ± 0.1 | | 31.6 ± 0.3
Day 23 | 32.7 ± 0.1 | | 33.2 ± 0.1 | 32.7 ± 0.2 | 32.6 ± 0.2 | 32.9 ± 0.1 | | 32.8 ± 0.3
Week 14 | 32.9 ± 0.1 | | 32.8 ± 0.1 | 32.8 ± 0.2 | 32.8 ± 0.2 | 32.6 ± 0.1 | | 32.8 ± 0.2
Platelets (10^3^/μL)
Day 3 | 825.2 ± 21.6 | | 807.4 ± 38.4 | 829.1 ± 23.7 | 845.2 ± 17.5 | 882.2 ± 31.2 | | 884.6 ± 40.1
Day 23 | 810.1 ± 28.1 | | 709.3 ± 34.9 | 810.9 ± 30.9 | 770.9 ± 23.6 | 806.2 ± 14.2 | | 778.4 ± 18.5
Week 14 | 682.1 ± 17.2 | | 653.8 ± 13.9 | 655.2 ± 16.7 | 675.0 ± 16.8 | 663.6 ± 10.9 | | 660.2 ± 13.5
Leukocytes (10^3^/μL)
Day 3 | 12.66 ± 0.55 | | 11.83 ± 0.65 | 12.15 ± 0.30 | 10.68 ± 0.53* | 7.83 ± 0.29** | | 6.38 ± 0.45**
Day 23 | 8.57 ± 0.38 | | 7.73 ± 0.45 | 7.86 ± 0.48 | 7.84 ± 0.80 | 7.58 ± 0.58 | | 6.33 ± 0.33**
Week 14 | 6.32 ± 0.46 | | 6.34 ± 0.23 | 7.58 ± 0.40 | 6.33 ± 0.30 | 7.04 ± 0.42 | | 7.34 ± 0.32
Segmented neutrophils (10^3^/μL)
Day 3 | 1.06 ± 0.05 | | 0.82 ± 0.04* | 0.90 ± 0.06* | 0.75 ± 0.03** | 0.66 ± 0.05** | | 0.65 ± 0.03**
Day 23 | 1.01 ± 0.10 | | 0.94 ± 0.10 | 0.81 ± 0.07 | 0.89 ± 0.11 | 0.99 ± 0.10 | | 0.93 ± 0.13
Week 14 | 1.08 ± 0.08 | | 1.20 ± 0.09 | 1.47 ± 0.15 | 1.26 ± 0.10 | 1.35 ± 0.08 | | 1.31 ± 0.05
Lymphocytes (10^3^/μL)
Day 3 | 11.22 ± 0.50 | | 10.65 ± 0.60 | 10.88 ± 0.28 | 9.60 ± 0.54* | 6.83 ± 0.26** | | 5.55 ± 0.43**
Day 23 | 7.33 ± 0.34 | | 6.54 ± 0.41 | 6.80 ± 0.42 | 6.76 ± 0.67 | 6.39 ± 0.50 | | 5.19 ± 0.34**
Week 14 | 5.06 ± 0.45 | | 4.96 ± 0.16 | 5.85 ± 0.34 | 4.86 ± 0.24 | 5.51 ± 0.42 | | 5.84 ± 0.29
Monocytes (10^3^/μL)
Day 3 | 0.24 ± 0.06 | | 0.23 ± 0.07 | 0.22 ± 0.05 | 0.19 ± 0.05 | 0.26 ± 0.04 | | 0.11 ± 0.02
Day 23 | 0.12 ± 0.03 | | 0.15 ± 0.03 | 0.14 ± 0.04 | 0.10 ± 0.04 | 0.09 ± 0.04 | | 0.14 ± 0.04
Week 14 | 0.09 ± 0.01 | | 0.08 ± 0.02 | 0.16 ± 0.05 | 0.12 ± 0.03 | 0.09 ± 0.02 | | 0.07 ± 0.02
Basophils (10^3^/μL)
Day 3 | 0.012 ± 0.003 | | 0.015 ± 0.004 | 0.012 ± 0.002 | 0.008 ± 0.002 | 0.008 ± 0.002 | | 0.004 ± 0.002*
Day 23 | 0.007 ± 0.002 | | 0.008 ± 0.002 | 0.003 ± 0.002 | 0.005 ± 0.002 | 0.002 ± 0.001* | | 0.000 ± 0.000**
Week 14 | 0.002 ± 0.001 | | 0.008 ± 0.007 | 0.010 ± 0.006 | 0.000 ± 0.000 | 0.013 ± 0.009 | | 0.002 ± 0.001
Eosinophils (10^3^/μL)
Day 3 | 0.14 ± 0.01 | | 0.13 ± 0.01 | 0.14 ± 0.02 | 0.13 ± 0.02 | 0.07 ± 0.00** | | 0.07 ± 0.01**
Day 23 | 0.11 ± 0.01 | | 0.10 ± 0.01 | 0.11 ± 0.01 | 0.09 ± 0.02 | 0.10 ± 0.02 | | 0.07 ± 0.01
Week 14 | 0.08 ± 0.02 | | 0.09 ± 0.02 | 0.10 ± 0.01 | 0.10 ± 0.01 | 0.08 ± 0.02 | | 0.12 ± 0.01
Immature neutrophils (10^3^/μL)
Day 3 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000
Day 23 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000
Week 14 | 0.000 ± 0.000 | | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | | 0.000 ± 0.000
Clinical Chemistry
n | 10 | | 10 | 10 | 10 | 10 | | 10
Urea nitrogen (mg/dL)
Day 3 | 10.4 ± 0.5 | | 9.0 ± 0.3 | 8.8 ± 0.5 | 10.4 ± 0.5 | 11.0 ± 0.4 | | 12.7 ± 0.5*
Day 23 | 11.6 ± 0.4 | | 11.4 ± 0.3 | 11.5 ± 0.3 | 11.5 ± 0.5 | 11.5 ± 0.4 | | 13.2 ± 0.6
Week 14 | 15.4 ± 0.4 | | 15.5 ± 0.7 | 15.2 ± 0.3 | 15.1 ± 0.4 | 15.5 ± 0.6 | | 13.2 ± 0.4**
Creatinine (mg/dL)
Day 3 | 0.53 ± 0.02 | | 0.50 ± 0.00 | 0.52 ± 0.01 | 0.54 ± 0.02 | 0.55 ± 0.02 | | 0.52 ± 0.01
Day 23 | 0.61 ± 0.01 | | 0.62 ± 0.02 | 0.65 ± 0.02 | 0.61 ± 0.01 | 0.62 ± 0.01 | | 0.65 ± 0.02
Week 14 | 0.63 ± 0.02 | | 0.67 ± 0.02 | 0.64 ± 0.02 | 0.62 ± 0.01 | 0.64 ± 0.02 | | 0.65 ± 0.02
Total protein (g/dL)
Day 3 | 6.0 ± 0.1 | | 6.0 ± 0.1 | 6.0 ± 0.1 | 6.1 ± 0.1 | 6.1 ± 0.1 | | 6.3 ± 0.0*
Day 23 | 6.3 ± 0.1 | | 6.2 ± 0.0 | 6.4 ± 0.1 | 6.4 ± 0.1 | 6.4 ± 0.1 | | 6.3 ± 0.1
Week 14 | 7.3 ± 0.1 | | 7.4 ± 0.1 | 7.3 ± 0.1 | 7.1 ± 0.1 | 7.2 ± 0.1 | | 6.5 ± 0.0**
Albumin (g/dL)
Day 3 | 4.5 ± 0.1 | | 4.5 ± 0.0 | 4.5 ± 0.0 | 4.5 ± 0.0 | 4.6 ± 0.0 | | 4.6 ± 0.0
Day 23 | 4.5 ± 0.0 | | 4.5 ± 0.0 | 4.6 ± 0.0 | 4.6 ± 0.1 | 4.6 ± 0.0 | | 4.4 ± 0.0
Week 14 | 5.1 ± 0.0 | | 5.1 ± 0.0 | 5.1 ± 0.0 | 5.0 ± 0.1 | 5.1 ± 0.1 | | 4.6 ± 0.0**
Globulin (g/dL)
Day 3 | 1.5 ± 0.0 | | 1.5 ± 0.0 | 1.5 ± 0.0 | 1.5 ± 0.0 | 1.5 ± 0.0 | | 1.6 ± 0.0
Day 23 | 1.8 ± 0.0 | | 1.7 ± 0.0 | 1.8 ± 0.0 | 1.8 ± 0.1 | 1.8 ± 0.0 | | 1.8 ± 0.1
Week 14 | 2.2 ± 0.0 | | 2.3 ± 0.0 | 2.2 ± 0.0 | 2.2 ± 0.1 | 2.2 ± 0.1 | | 1.9 ± 0.0**
A/G ratio
Day 3 | 3.0 ± 0.1 | | 3.0 ± 0.1 | 2.9 ± 0.1 | 3.0 ± 0.1 | 3.0 ± 0.0 | | 2.9 ± 0.1
Day 23 | 2.6 ± 0.0 | | 2.6 ± 0.0 | 2.5 ± 0.0 | 2.5 ± 0.1 | 2.5 ± 0.0 | | 2.4 ± 0.1
Week 14 | 2.3 ± 0.0 | | 2.2 ± 0.0 | 2.3 ± 0.0 | 2.3 ± 0.0 | 2.3 ± 0.0 | | 2.4 ± 0.0
Alanine aminotransferase (IU/L)
Day 3 | 50 ± 2 | | 45 ± 2 | 47 ± 1 | 46 ± 1 | 42 ± 1** | | 42 ± 1**
Day 23 | 35 ± 1 | | 36 ± 1 | 38 ± 2 | 38 ± 1 | 36 ± 1 | | 38 ± 2
Week 14 | 52 ± 2 | | 64 ± 5 | 63 ± 7 | 58 ± 4 | 58 ± 6 | | 46 ± 2
Alkaline phosphatase (IU/L)
Day 3 | 566 ± 15 | | 521 ± 11 | 532 ± 12 | 536 ± 13 | 501 ± 10** | | 480 ± 13**
Day 23 | 334 ± 6 | | 316 ± 7 | 327 ± 9 | 327 ± 6 | 315 ± 8 | | 340 ± 10
Week 14 | 211 ± 6 | | 206 ± 8 | 198 ± 9 | 197 ± 6 | 191 ± 8 | | 198 ± 9
Creatine kinase (IU/L)
Day 3 | 380 ± 21 | | 384 ± 26 | 496 ± 40 | 593 ± 121 | 452 ± 32 | | 469 ± 55
Day 23 | 294 ± 25 | | 400 ± 68 | 310 ± 26^b^ | 344 ± 42 | 421 ± 66 | | 353 ± 41
Week 14 | 277 ± 20 | | 305 ± 58 | 377 ± 80 | 606 ± 121 | 385 ± 98 | | 436 ± 132
Sorbitol dehydrogenase (IU/L)
Day 3 | 16 ± 1 | | 15 ± 1 | 17 ± 1 | 15 ± 1 | 15 ± 1 | | 14 ± 1
Day 23 | 14 ± 1 | | 13 ± 1 | 14 ± 1 | 13 ± 0 | 14 ± 1 | | 17 ± 1
Week 14 | 16 ± 1 | | 17 ± 1 | 15 ± 1 | 16 ± 1 | 17 ± 1 | | 16 ± 1
Bile salts (µmol/L)
Day 3 | 7.0 ± 1.4 | | 7.2 ± 1.1 | 7.5 ± 1.5 | 7.2 ± 0.9 | 7.2 ± 0.6 | | 5.4 ± 0.4
Day 23 | 6.8 ± 0.9 | | 5.9 ± 0.7 | 7.4 ± 1.5 | 5.3 ± 0.4 | 5.2 ± 0.6 | | 5.7 ± 0.6
Week 14 | 5.0 ± 0.2 | | 7.7 ± 1.7 | 9.9 ± 2.3 | 6.9 ± 0.6 | 7.0 ± 1.9 | | 8.5 ± 1.5

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

Table C-2 Hematology Data for Mice in the Three-month Inhalation Study of Triethylamine^a^

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm | 200 ppm
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Hematocrit (spun) (%) | 49.9 ± 0.3 | 50.6 ± 0.5 | 50.2 ± 0.5 | 50.4 ± 0.4 | 50.3 ± 0.3 | 50.2 ± 0.4
Hematocrit (mL/dL) | 50.3 ± 0.3 | 51.5 ± 0.4 | 50.9 ± 0.5 | 50.6 ± 0.3 | 50.7 ± 0.3 | 50.4 ± 0.6
Hemoglobin (g/dL) | 16.0 ± 0.1 | 16.4 ± 0.1 | 16.1 ± 0.1 | 16.2 ± 0.1 | 16.1 ± 0.1 | 16.2 ± 0.1
Erythrocytes (10^6^/µL) | 10.41 ± 0.08 | 10.62 ± 0.08 | 10.53 ± 0.09 | 10.40 ± 0.11 | 10.51 ± 0.06 | 10.41 ± 0.13
Reticulocytes (10^3^/µL) | 164.0 ± 15.1 | 176.0 ± 14.4 | 150.9 ± 11.9 | 163.3 ± 8.8 | 175.2 ± 20.0 | 147.6 ± 11.9
Nucleated erythrocytes /100 erythrocytes | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.10 ± 0.10
Mean cell volume (fL) | 48.4 ± 0.2 | 48.5 ± 0.2 | 48.3 ± 0.1 | 48.6 ± 0.4 | 48.2 ± 0.1 | 48.5 ± 0.2
Mean cell hemoglobin (pg) | 15.3 ± 0.1 | 15.4 ± 0.0 | 15.3 ± 0.0 | 15.6 ± 0.1 | 15.3 ± 0.0 | 15.6 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 31.7 ± 0.1 | 31.8 ± 0.1 | 31.7 ± 0.1 | 32.0 ± 0.2 | 31.8 ± 0.1 | 32.1 ± 0.3
Platelets (10^3^/µL) | 919.2 ± 19.5 | 851.3 ± 35.7 | 923.2 ± 15.7 | 893.9 ± 19.9 | 879.6 ± 21.1 | 839.7 ± 36.5
Leukocytes (10^3^/µL) | 3.94 ± 0.49 | 3.16 ± 0.36 | 3.81 ± 0.33 | 3.87 ± 0.34 | 3.61 ± 0.20 | 3.94 ± 0.40
Segmented neutrophils (10^3^/µL) | 0.58 ± 0.07 | 0.48 ± 0.06 | 0.51 ± 0.04 | 0.54 ± 0.05 | 0.49 ± 0.03 | 0.51 ± 0.06
Lymphocytes (10^3^/µL) | 3.23 ± 0.41 | 2.59 ± 0.30 | 3.17 ± 0.27 | 3.21 ± 0.29 | 3.02 ± 0.18 | 3.29 ± 0.33
Monocytes (10^3^/µL) | 0.03 ± 0.02 | 0.02 ± 0.00 | 0.04 ± 0.02 | 0.02 ± 0.00 | 0.02 ± 0.01 | 0.05 ± 0.02
Basophils (10^3^/µL) | 0.016 ± 0.007 | 0.009 ± 0.002 | 0.018 ± 0.004 | 0.012 ± 0.001 | 0.016 ± 0.002 | 0.014 ± 0.003
Eosinophils (10^3^/µL) | 0.09 ± 0.02 | 0.07 ± 0.02 | 0.07 ± 0.01 | 0.08 ± 0.02 | 0.07 ± 0.01 | 0.08 ± 0.01
Howell-Jolly bodies (% erythrocytes) | 0.13 ± 0.03 | 0.05 ± 0.02 | 0.10 ± 0.03 | 0.16 ± 0.04 | 0.12 ± 0.03 | 0.13 ± 0.04
Immature neutrophils (10^3^/µL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Female
Hematocrit (spun) (%) | 49.9 ± 0.4 | 50.3 ± 0.3 | 50.1 ± 0.4 | 50.1 ± 0.4 | 49.3 ± 0.4 | 50.0 ± 0.4
Hematocrit (mL/dL) | 50.2 ± 0.6 | 51.0 ± 0.3 | 50.6 ± 0.4 | 50.5 ± 0.4 | 49.7 ± 0.4 | 50.2 ± 0.4
Hemoglobin (g/dL) | 16.1 ± 0.2 | 16.4 ± 0.1 | 16.2 ± 0.1 | 16.2 ± 0.1 | 15.9 ± 0.1 | 16.1 ± 0.1
Erythrocytes (10^6^/µL) | 10.25 ± 0.12 | 10.41 ± 0.06 | 10.21 ± 0.11 | 10.26 ± 0.08 | 10.06 ± 0.10 | 10.22 ± 0.07
Reticulocytes (10^3^/µL) | 171.4 ± 18.9 | 196.8 ± 18.9 | 198.3 ± 19.7 | 202.8 ± 16.8 | 188.1 ± 10.8 | 173.9 ± 17.3
Nucleated erythrocytes /100 erythrocytes | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 49.0 ± 0.2 | 49.0 ± 0.3 | 49.6 ± 0.2 | 49.2 ± 0.2 | 49.5 ± 0.2 | 49.2 ± 0.1
Mean cell hemoglobin (pg) | 15.8 ± 0.1 | 15.7 ± 0.1 | 15.9 ± 0.1 | 15.8 ± 0.0 | 15.9 ± 0.1 | 15.8 ± 0.0
Mean cell hemoglobin concentration (g/dL) | 32.2 ± 0.1 | 32.0 ± 0.2 | 32.0 ± 0.1 | 32.1 ± 0.1 | 32.1 ± 0.1 | 32.1 ± 0.1
Platelets (10^3^/µL) | 834.6 ± 19.7 | 820.3 ± 14.8 | 811.7 ± 17.5 | 820.2 ± 8.8 | 842.3 ± 19.0 | 783.9 ± 23.0
Leukocytes (10^3^/µL) | 3.31 ± 0.14 | 3.96 ± 0.36 | 3.07 ± 0.23 | 3.66 ± 0.71 | 3.36 ± 0.43 | 3.49 ± 0.32
Segmented neutrophils (10^3^/µL) | 0.37 ± 0.04 | 0.50 ± 0.07 | 0.40 ± 0.05 | 0.44 ± 0.08 | 0.42 ± 0.06 | 0.36 ± 0.03
Lymphocytes (10^3^/µL) | 2.87 ± 0.14 | 3.36 ± 0.30 | 2.57 ± 0.19 | 3.15 ± 0.65 | 2.86 ± 0.38 | 3.03 ± 0.29
Monocytes (10^3^/µL) | 0.03 ± 0.01 | 0.02 ± 0.01 | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.02 ± 0.01 | 0.03 ± 0.01
Basophils (10^3^/µL) | 0.012 ± 0.003 | 0.021 ± 0.005 | 0.016 ± 0.004 | 0.015 ± 0.003 | 0.015 ± 0.005 | 0.021 ± 0.004
Eosinophils (10^3^/µL) | 0.04 ± 0.00 | 0.06 ± 0.01 | 0.05 ± 0.01 | 0.04 ± 0.01 | 0.05 ± 0.01 | 0.05 ± 0.01
Howell-Jolly bodies (% erythrocytes) | 0.05 ± 0.02 | 0.10 ± 0.03 | 0.08 ± 0.02 | 0.09 ± 0.02 | 0.13 ± 0.03 | 0.07 ± 0.02
Immature neutrophils (10^3^/µL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.