# Appendix B Genetic Toxicology

Table B-1 Mutagenicity of Triethylamine in Bacterial Tester Strains^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% Hamster S9 | With 10% Hamster S9 | With 10% Rat S9 | With 10% Rat S9
TA100
| 0 | 125 ± 1 | 104 ± 5 | 160 ± 13 | 117 ± 5 | 142 ± 6 | 127 ± 10
| 100 | 114 ± 7 | 117 ± 10 | 125 ± 10 | 123 ± 3 | 127 ± 6 | 112 ± 9
| 333 | 133 ± 10 | 115 ± 15 | 147 ± 1 | 158 ± 5 | 127 ± 12 | 113 ± 3
| 1,000 | 110 ± 4 | 113 ± 15 | 138 ± 7 | 128 ± 11 | 125 ± 17 | 111 ± 8
| 3,333 | 112 ± 5 | 92 ± 7 | 140 ± 7 | 138 ± 15 | 119 ± 15 | 89 ± 3
| 10,000 | Toxic | Toxic | 129 ± 1 | Toxic | 120 ± 31 | Toxic
Trial summary | | Negative | Negative | Negative | Equivocal | Negative | Negative
Positive control^b^ | | 277 ± 18 | 419 ± 13 | 1,100 ± 19 | 778 ± 10 | 688 ± 39 | 335 ± 6
TA1535
| 0 | 27 ± 1 | 32 ± 2 | 33 ± 3 | 35 ± 4 | 31 ± 3 | 24 ± 1
| 100 | 21 ± 3 | 30 ± 4 | 26 ± 3 | 26 ± 3 | 25 ± 3 | 22 ± 1
| 333 | 22 ± 4 | 24 ± 2 | 25 ± 2 | 30 ± 3 | 23 ± 3 | 24 ± 2
| 1,000 | 22 ± 2 | 32 ± 5 | 25 ± 1 | 33 ± 11 | 22 ± 2 | 18 ± 2
| 3,333 | 20 ± 4 | 21 ± 4 | 24 ± 1 | 42 ± 5 | 17 ± 2 | 17 ± 2
| 10,000 | Toxic | Toxic | 27 ± 6 | Toxic | 15 ± 4 | 4 ± 2
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 315 ± 15 | 379 ± 22 | 357 ± 18 | 356 ± 53 | 260 ± 8 | 120 ± 13
TA1537
| 0 | 4 ± 1 | 6 ± 1 | 7 ± 0 | 7 ± 1 | 9 ± 2 | 15 ± 1
| 100 | 3 ± 1 | 8 ± 1 | 7 ± 1 | 6 ± 1 | 12 ± 2 | 9 ± 0
| 333 | 5 ± 1 | 8 ± 2 | 4 ± 1 | 6 ± 1 | 11 ± 2 | 6 ± 0
| 1,000 | 4 ± 1 | 5 ± 1 | 5 ± 1 | 9 ± 3 | 11 ± 3 | 9 ± 1
| 3,333 | 6 ± 2 | 6 ± 1 | 8 ± 3 | 8 ± 1 | 6 ± 1 | 5 ± 2
| 10,000 | Toxic | Toxic | 7 ± 1 | 3 ± 2 | 7 ± 1 | 2 ± 0
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 110 ± 7 | 277 ± 25 | 446 ± 16 | 454 ± 18 | 217 ± 5 | 204 ± 15
TA98
| 0 | 22 ± 2 | 18 ± 4 | 32 ± 2 | 26 ± 3 | 34 ± 3 | 33 ± 4
| 100 | 20 ± 2 | 29 ± 5 | 31 ± 5 | 35 ± 5 | 33 ± 4 | 26 ± 5
| 333 | 18 ± 1 | 18 ± 2 | 34 ± 4 | 32 ± 6 | 25 ± 6 | 26 ± 3
| 1,000 | 20 ± 1 | 19 ± 2 | 31 ± 6 | 24 ± 2 | 26 ± 4 | 29 ± 1
| 3,333 | 23 ± 7 | 12 ± 1 | 28 ± 4 | 34 ± 4 | 26 ± 1 | 15 ± 5
| 10,000 | Toxic | Toxic | 30 ± 0 | Toxic | 22 ± 3 | Toxic
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive Control | | 654 ± 55 | 730 ± 19 | 926 ± 12 | 457 ± 34 | 462 ± 38 | 401 ± 33

^a^ Study was performed at SRI International. Data are presented as revertants/plate (mean ± standard error) from three plates. The detailed protocol and these data are presented by Zeiger et al.^39^ 0 μg/plate was the solvent control.

^b^ The positive controls in the absence of metabolic activation were sodium azide (TA100 and TA1535), 9-aminoacridine (TA1537), and 4-nitro-o-phenylenediamine (TA98). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table B-2 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Treatment with Triethylamine by Inhalation for Three Months^a^

| Concentration (ppm) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%)
Male
Air^d^ | | 10 | 1.65 ± 0.28 | | 3.03 ± 0.17
Triethylamine | 12.5 | 10 | 1.90 ± 0.43 | 0.2763 | 3.02 ± 0.25
| 25 | 10 | 1.90 ± 0.21 | 0.2763 | 2.78 ± 0.19
| 50 | 10 | 2.65 ± 0.47 | 0.0154 | 2.79 ± 0.24
| 100 | 10 | 2.45 ± 0.35 | 0.0385 | 2.47 ± 0.18
| 200 | 10 | 2.75 ± 0.37 | 0.0094 | 3.14 ± 0.48
| | | P = 0.006^e^
Female
Air | | 10 | 2.32 ± 0.44 | | 2.94 ± 0.29
Triethylamine | 12.5 | 10 | 1.05 ± 0.28 | 0.9927 | 2.71 ± 0.24
| 25 | 10 | 2.30 ± 0.40 | 0.5103 | 2.61 ± 0.22
| 50 | 10 | 1.55 ± 0.37 | 0.9156 | 3.14 ± 0.15
| 100 | 10 | 1.95 ± 0.34 | 0.7339 | 3.18 ± 0.31
| 200 | 10 | 1.85 ± 0.45 | 0.7897 | 3.06 ± 0.29
| | | P = 0.480

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by MacGregor et al.^57^ NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the chamber control group, significant at P ≤ 0.005.

^d^ Chamber control.

^e^ Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test; significant at P ≤ 0.025.