# Appendix A Summary of Nonneoplastic Lesions in Rats and Mice

Table A-1 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Three-month Inhalation Study of Triethylamine^a^

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm | 200 ppm
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal kill | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10) | (10) | (10)
Clear cell focus | – | – | – | – | 1 (10%) | –
Hepatodiaphragmatic nodule | – | 3 (30%) | 4 (40%) | – | – | 1 (10%)
Inflammation | – | – | – | 2 (20%) | – | –
Bile duct, hyperplasia, focal | – | – | 1 (10%) | – | – | –
Cardiovascular System
None | – | – | – | – | – | –
Endocrine System
None | – | – | – | – | – | –
General Body System
None | – | – | – | – | – | –
Genital System
Prostate | (10) | – | – | – | – | (10)
Inflammation, suppurative | 1 (10%) | – | – | – | – | –
Hematopoietic System
Lymph node, mediastinal | (7) | – | – | – | – | (2)
Ectasia | 1 (14%) | – | – | – | – | –
Integumentary System
None | – | – | – | – | – | –
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System
Larynx | (10) | (10) | (10) | (10) | (10) | (10)
Infiltration cellular, mononuclear cell | – | 3 (30%) | – | 1 (10%) | – | –
Inflammation | – | – | – | 1 (10%) | – | –
Glands, inflammation, suppurative | – | – | – | – | 1 (10%) | –
Squamous epithelium, metaplasia | – | 1 (10%) | – | 1 (10%) | – | –
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, focal | – | – | – | 1 (10%) | – | –
Metaplasia, osseous | 2 (20%) | – | 2 (20%) | 2 (20%) | 1 (10%) | –
Alveolar epithelium, hyperplasia | 1 (10%) | – | – | – | – | –
Alveolar epithelium, infiltration cellular, polymorphonuclear | 1 (10%) | – | – | – | – | –
Alveolus, infiltration cellular, histiocyte | 4 (40%) | 5 (50%) | 3 (30%) | 2 (20%) | 6 (60%) | 6 (60%)
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Olfactory epithelium, atrophy | – | – | – | 10 (100%) | 10 (100%) | 10 (100%)
Respiratory epithelium, accumulation, hyaline droplet | – | – | – | – | – | 3 (30%)
Respiratory epithelium, hyperplasia | – | 3 (30%) | 9 (90%) | 9 (90%) | 10 (100%) | 10 (100%)
Special Senses System
Eye | (9) | (10) | (10) | (10) | (10) | (10)
Cornea, mineralization | – | – | – | – | 1 (10%) | 3 (30%)
Cornea, necrosis | – | – | – | – | – | 1 (10%)
Cornea, epithelium, vacuolation | – | – | – | – | – | 2 (20%)
Retina, degeneration | – | – | – | 1 (10%) | – | –
Harderian gland | (10) | – | – | – | (1) | (10)
Infiltration cellular, mononuclear cell | 1 (10%) | – | – | – | 1 (100%) | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10) | (10) | (10)
Nephropathy | 1 (10%) | – | 1 (10%) | – | 1 (10%) | –
Renal tubule, cyst | – | – | – | 1 (10%) | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-2 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Three-month Inhalation Study of Triethylamine^a^

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm | 200 ppm
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Intestine small, jejunum | (10) | (10) | (10) | (10) | (10) | (10)
Serosa, inflammation, chronic | – | 1 (10%) | – | – | – | –
Liver | (10) | (10) | (10) | (10) | (10) | (10)
Hepatodiaphragmatic nodule | 1 (10%) | – | – | 1 (10%) | 1 (10%) | 2 (20%)
Inflammation | 1 (10%) | – | 2 (20%) | 2 (20%) | 1 (10%) | 1 (10%)
Inflammation, chronic | – | 1 (10%) | – | – | – | –
Serosa, fibrosis | – | – | – | – | 1 (10%) | –
Mesentery | – | – | (2) | (1) | – | –
Fat, necrosis, chronic | – | – | 2 (100%) | 1 (100%) | – | –
Pancreas | (10) | – | – | – | – | (10)
Atrophy | 1 (10%) | – | – | – | – | –
Stomach, glandular | (10) | (10) | (10) | (10) | (10) | (10)
Cyst | – | – | – | – | – | 1 (10%)
Cardiovascular System
Heart | (10) | – | – | – | (1) | (10)
Pericardium, fibrosis | – | – | – | – | 1 (100%) | –
Pericardium, infiltration cellular, mononuclear cell | – | – | – | – | 1 (100%) | –
Endocrine System
None | – | – | – | – | – | –
General Body System
None | – | – | – | – | – | –
Genital System
Ovary | (10) | – | (1) | (1) | (1) | (10)
Metaplasia, lipocyte | 1 (10%) | – | – | – | – | –
Periovarian tissue, cyst | – | – | 1 (100%) | 1 (100%) | 1 (100%) | 1 (10%)
Hematopoietic System
Lymph node | – | (1) | – | (1) | (1) | –
Pancreatic, hyperplasia, histiocytic | – | 1 (100%) | – | 1 (100%) | 1 (100%) | –
Integumentary System
None | – | – | – | – | – | –
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System
Larynx | (9) | (10) | (10) | (10) | (10) | (10)
Granuloma | – | – | – | 1 (10%) | – | –
Infiltration, cellular, mononuclear cell | – | 1 (10%) | 1 (10%) | – | – | –
Inflammation | – | 1 (10%) | – | – | – | –
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, focal | – | – | – | – | – | 1 (10%)
Metaplasia, osseous | – | – | – | – | – | 1 (10%)
Mineralization | – | – | – | – | – | 1 (10%)
Alveolar epithelium, hyperplasia | 1 (10%) | – | – | – | – | –
Alveolus, infiltration cellular, histiocyte | 2 (20%) | 1 (10%) | 4 (40%) | 4 (40%) | 7 (70%) | 7 (70%)
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Foreign body | 1 (10%) | – | – | – | – | –
Inflammation, chronic | – | – | – | 1 (10%) | 2 (20%) | –
Olfactory epithelium, atrophy | – | – | 4 (40%) | 10 (100%) | 10 (100%) | 10 (100%)
Respiratory epithelium, accumulation, hyaline droplet | – | – | – | – | 1 (10%) | –
Respiratory epithelium, hyperplasia | – | 3 (30%) | 9 (90%) | 10 (100%) | 10 (100%) | 10 (100%)
Pleura | – | – | – | – | (1) | –
Hyperplasia | – | – | – | – | 1 (100%) | –
Inflammation, chronic | – | – | – | – | 1 (100%) | –
Special Senses System
Eye | (10) | (10) | (10) | (10) | (10) | (10)
Anterior chamber, infiltration cellular, macrophage | – | – | – | – | – | 1 (10%)
Cornea, edema | – | – | – | – | – | 1 (10%)
Cornea, inflammation, chronic | – | – | – | – | – | 1 (10%)
Cornea, mineralization | – | – | – | – | – | 2 (20%)
Cornea, necrosis | – | – | – | – | – | 1 (10%)
Cornea, vesicle, subepithelial | – | – | – | – | – | 3 (30%)
Cornea, epithelium, ulcer | – | – | – | – | – | 1 (10%)
Lens, cataract | – | – | – | – | – | 1 (10%)
Retina, degeneration | – | – | 1 (10%) | – | 2 (20%) | 1 (10%)
Retina, dysplasia | – | – | – | – | – | 1 (10%)
Harderian gland | (10) | – | – | – | – | (10)
Infiltration cellular, mononuclear cell | 1 (10%) | – | – | – | – | 3 (30%)
Urinary System
None | – | – | – | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-3 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Three-month Inhalation Study of Triethylamine^a^

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm | 200 ppm
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
None | – | – | – | – | – | –
Cardiovascular System
None | – | – | – | – | – | –
Endocrine System
None | – | – | – | – | – | –
General Body System
None | – | – | – | – | – | –
Genital System
None | – | – | – | – | – | –
Hematopoietic System
None | – | – | – | – | – | –
Integumentary System
None | – | – | – | – | – | –
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Infiltration cellular, histiocyte | – | 1 (10%) | – | – | – | –
Inflammation, chronic active | 1 (10%) | – | – | – | – | –
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, suppurative | – | – | – | – | – | 1 (10%)
Olfactory epithelium, accumulation, hyaline droplet | – | – | – | 1 (10%) | 6 (60%) | –
Olfactory epithelium, atrophy | – | – | – | 9 (90%) | 10 (100%) | 10 (100%)
Olfactory epithelium, vacuolization cytoplasmic | – | – | – | 6 (60%) | – | –
Respiratory epithelium, accumulation, hyaline droplet | – | – | – | – | 9 (90%) | –
Respiratory epithelium, metaplasia, squamous | – | – | – | – | – | 10 (100%)
Turbinate, atrophy | – | – | – | – | – | 5 (50%)
Turbinate, hyperostosis | – | 10 (100%) | 9 (90%) | 10 (100%) | 10 (100%) | 10 (100%)
Turbinate, necrosis | – | – | – | – | – | 10 (100%)
Special Senses System
None | – | – | – | – | – | –
Urinary System
None | – | – | – | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-4 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Three-month Inhalation Study of Triethylamine^a^

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm | 200 ppm
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal kill | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
None | – | – | – | – | – | –
Cardiovascular System
None | – | – | – | – | – | –
Endocrine System
None | – | – | – | – | – | –
General Body System
None | – | – | – | – | – | –
Genital System
Uterus | (10) | – | – | – | (1) | (10)
Decidual reaction | – | – | – | – | 1 (100%) | –
Hematopoietic System
None | – | – | – | – | – | –
Integumentary System
None | – | – | – | – | – | –
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System
Nose | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, suppurative | – | – | – | – | – | 1 (10%)
Olfactory epithelium, accumulation, hyaline droplet | – | – | – | 7 (70%) | 10 (100%) | 8 (80%)
Olfactory epithelium, atrophy | – | – | – | 10 (100%) | 10 (100%) | 10 (100%)
Olfactory epithelium, vacuolization cytoplasmic | – | – | – | 5 (50%) | – | –
Respiratory epithelium, accumulation, hyaline droplet | – | – | – | 7 (70%) | 10 (100%) | 8 (80%)
Respiratory epithelium, metaplasia, squamous | – | – | – | – | – | 9 (90%)
Turbinate, atrophy | – | – | – | – | – | 3 (30%)
Turbinate, hyperostosis | – | 8 (80%) | 10 (100%) | 10 (100%) | 9 (90%) | 10 (100%)
Turbinate, necrosis | – | – | – | – | – | 10 (100%)
Special Senses System
None | – | – | – | – | – | –
Urinary System
None | – | – | – | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.