# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8992

DOI: https://doi.org/10.22427/NTP-TOX-77

Report Series: NTP Toxicity Report Series

Report Series Number: 77

Official citation: National Toxicology Program (NTP). 2021. NTP technical report on the toxicity studies of hexachlorobenzene (CASRN 118-74-1) administered by gavage to female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats. Research Triangle Park, NC: National Toxicology Program: Toxicity Report 77.