# Peer Review

The National Toxicology Program (NTP) conducted a peer review of the draft NTP Technical Report on the Toxicity Studies of Hexachlorobenzene (CASRN 118-74-1) Administered by Gavage to Female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats by letter in May 2020 by the experts listed below. Reviewer selection and document review followed established NTP practices. The reviewers were charged to:

1. Peer review the draft NTP Technical Report on the Toxicity Studies of Hexachlorobenzene Administered by Gavage to Female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats.
2. Comment on NTP’s interpretations of the data.

NTP carefully considered reviewer comments in finalizing this report.

## Peer Reviewers

- Nathaniel D. Collins, Ph.D.
  Executive Director, Drug Safety Evaluation
  Bristol Myers Squibb
  Bridgewater, New Jersey, USA
- Charles E. Wood, Ph.D.
  Senior Principal Pathologist and Molecular Pathology Lead
  Boehringer Ingelheim Pharmaceuticals, Inc.
  Redding, Connecticut, USA