# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Designed studies, evaluated and interpreted results, and reported findings
  M.C. Huang, Ph.D., Study Scientist
  C.R. Blystone, Ph.D.
  M.C. Cora, Ph.D.
  H.C. Cunny, Ph.D.
  M.J. DeVito, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  D.E. Malarkey, D.V.M., Ph.D.
  G.K. Roberts, Ph.D.
  K.R. Shockley, Ph.D.
  G.S. Travlos, D.V.M.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Provided oversight for data management
  J.M. Fostel, Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  R.C. Kovi, M.V.Sc., Ph.D., Study Pathologist
- Provided pathology review
  N. Allison, D.V.M., Ph.D.
  J.C. Peckham, D.V.M., Ph.D.
  G.A. Willson, B.V.M.S.
- Battelle, Columbus, Ohio, USA
  Conducted studies and evaluated pathology findings
  M.R. Hejtmancik, Ph.D., Principal Investigator
  S.W. Graves, B.S.
  J.D. Johnson, Ph.D.
  T.A. Peace, D.V.M.
  D.Y. Vasconcelos, D.V.M., Ph.D.
- Conducted prestart chemistry activities and dose formulations
  B.L. Burback, Ph.D.
  S.W. Graves, B.S.
- MRIGlobal, Kansas City, Missouri, USA
  Conducted prestart chemistry activities, dose formulations, and biological sample analyses
  R. Harris, Ph.D., Principal Investigator
  A.P. Clark, B.S.E.
  M. Kozak, B.G.S.
  A. Shan, M.S.
  K.D. White, B.S.
- Pathology Associates, A Division of Charles River Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Working Group (July 9, 2002)
  P.H. Long, D.V.M., Ph.D.
- ASRC Federal, Research Triangle Park, North Carolina, USA
  Prepared data for report
  P. Brown, B.S.
  H. Gong, M.S.
  C. Martini, B.S.
  C. Myers, M.S.
  N. Sayers, B.S.
  M. Shaw, B.S.
  R. Whittlesey, M.S.