# References

1 International Programme on Chemical Safety (IPCS). Environmental Health Criteria 195: Hexachlorobenzene. Geneva, Switzerland: World Health Organization; 1997. http://www.inchem.org/documents/ehc/ehc/ehc195.htm#SectionNumber:2.2 [Accessed: March 14, 2011]
2 O’Neil MJ. The Merck Index. 14th ed. Whitehouse Station, NJ: Merck & Company; 2006. p. 808.
3 Agency for Toxic Substances and Disease Registry (ATSDR). Toxicological profile for hexachlorobenzene. Atlanta, GA: U.S. Department of Health and Human Services, Public Health Service, Agency for Toxic Substances and Disease Registry; 2002. https://www.atsdr.cdc.gov/ToxProfiles/tp90.pdf [Accessed: March 14, 2011]
4 Tiernan TO, Taylor ML, Garrett JH, VanNess GF, Solch JG, Wagel DJ, Ferguson GL, Schecter A. Sources and fate of polychlorinated dibenzodioxins, dibenzofurans and related compounds in human environments. Environ Health Perspect. 1985;59:145–158. 10.1289/ehp.59-1568078 3921357
5 Bailey RE. Global hexachlorobenzene emissions. Chemosphere. 2001; 43(2):167–182. 10.1016/S0045-6535(00)00186-7 11297396
6 Rippen G, Frank R. Estimation of hexachlorobenzene pathways from the technosphere into the environment. IARC Sci Publ. 1986;(77):45–52. 3596738
7 International Agency for Research on Cancer (IARC). Hexachlorobenzene. Vol. 20. Lyon, France: IARC; 1979. p. 155–178. (IARC monograph on the evaluation of the carcinogenic risk of chemicals to humans: Some halogenated hydrocarbons).
8 Jacoff FS, Scarberry R, Rosa D. Source assessment of hexachlorobenzene from the organic chemical manufacturing industry. IARC Sci Publ. 1986;(77):31–37. 3596719
9 Ritter L, Solomon KR, Forget J, Stemeroff M, O’Leary C. A review of selected persistent organic pollutants: DDT-aldrin-dieldrin-endrin-chlordane, heptachlor-hexachlorobenzene-mïrex-toxaphene, polychlorinated biphenyls, dioxins and furans Geneva. Switzerland: Prepared for the International Programme on Chemical Safety, Inter-Organization Programme for the Sound Management of Chemicals; 1995. https://www.who.int/ipcs/assessment/en/pcs_95_39_2004_05_13.pdf, PCS/95.39.
10 U. S. Environmental Protection Agency (USEPA). Toxic Release Inventory. Washington, DC; 2012. https://www.epa.gov/tri [Accessed: May 10, 2012]
11 United States Food and Drug Administration (FDA). Total diet study: Market baskets 1991-3 through 2003-4. College Park, MD: United States Food and Drug Administration, Center for Food Safety and Applied Nutrition, Office of Food Safety; 2006. https://www.fda.gov/media/77962/download
12 Gunderson EL. FDA Total Diet Study, July 1986-April 1991, dietary intakes of pesticides, selected elements, and other chemicals. J AOAC Int. 1995; 78(6):1353–1363. 10.1093/jaoac/78.6.1353 8664570
13 U. S. Department of Agriculture (USDA). Pesticide Data Program: Annual summary, calendar year 2007. Washington, DC: U.S. Department of Agriculture, Agriculture Marketing Service; 2008. https://web.archive.org/web/20111024232422/http://www.ams.usda.gov/AMSv1.0/getfile?dDocName=STELPRDC5074338 [Accessed: March 10, 2011]
14 Patterson DG Jr, Wong LY, Turner WE, Caudill SP, Dipietro ES, McClure PC, Cash TP, Osterloh JD, Pirkle JL, Sampson EJ, et al. Levels in the U.S. population of those persistent organic pollutants (2003-2004) included in the Stockholm Convention or in other long range transboundary air pollution agreements. Environ Sci Technol. 2009; 43(4):1211–1218. 10.1021/es801966w 19320182
15 Centers for Disease Control and Prevention (CDC). Fourth national report on human exposure to environmental chemicals: Updated tables, January 2019. Vol 2. Atlanta, GA: United States Department of Health and Human Services, Centers for Disease Control and Prevention; 2019. https://www.cdc.gov/exposurereport/pdf/FourthReport_UpdatedTables_Volume2_Jan2019-508.pdf
16 Weldon RH, Webster M, Harley KG, Bradman A, Fenster L, Davis MD, Hubbard A, Barr DB, Holland N, Eskenazi B. Serum persistent organic pollutants and duration of lactation among Mexican-American women. J Environ Public Health. 2010;2010:1–11. 10.1155/2010/861757 20671963
17 Dallaire F, Dewailly Ã, Muckle G, Ayotte P. Time trends of persistent organic pollutants and heavy metals in umbilical cord blood of Inuit infants born in Nunavik (Quebec, Canada) between 1994 and 2001. Environ Health Perspect. 2003; 111(13):1660–1664. 10.1289/ehp.6269 14527847
18 Polder A, Thomsen C, Lindstrom G, Loken KB, Skaare JU. Levels and temporal trends of chlorinated pesticides, polychlorinated biphenyls and brominated flame retardants in individual human breast milk samples from Northern and Southern Norway. Chemosphere. 2008; 73(1):14–23. 10.1016/j.chemosphere.2008.06.002 18653208
19 Hardell E, Carlberg M, Nordstrom M, van Bavel B. Time trends of persistent organic pollutants in Sweden during 1993-2007 and relation to age, gender, body mass index, breast-feeding and parity. Sci Total Environ. 2010; 408(20):4412–4419. 10.1016/j.scitotenv.2010.06.029 20643475
20 Bleavins MR, Breslin WJ, Aulerich RJ, Ringer RK. Excretion and placental and mammary transfer of hexachlorobenzene in the European ferret (Mustela putorius furo). J Toxicol Environ Health A. 1982; 10(6):929–940. 10.1080/15287398209530307 7161840
21 Scheufler E, Rozman KK. Comparative decontamination of hexachlorobenzene-exposed rats and rabbits by hexadecane. J Toxicol Environ Health. 1984; 14(2-3):353–362. 10.1080/15287398409530585 6502739
22 Bailey J, Knauf V, Mueller W, Hobson W. Transfer of hexachlorobenzene and polychlorinated biphenyls to nursing infant rhesus monkeys: Enhanced toxicity. Environ Res. 1980; 21(1):190–196. 10.1016/0013-9351(80)90021-3 6771134
23 Goldey ES, Taylor DH. Developmental neurotoxicity following premating maternal exposure to hexachlorobenzene in rats. Neurotoxicol Teratol. 1992; 14(1):15–21. 10.1016/0892-0362(92)90024-5 1593975
24 Nakashima Y, Ohsawa S, Umegaki K, Ikegami S. Hexachlorobenzene accumulated by dams during pregnancy is transferred to suckling rats during early lactation. J Nutr. 1997; 127(4):648–654. 10.1093/jn/127.4.648 9109618
25 Nakashima Y, Ohsawa S, Ikegami S. High-Fat diet enhances accumulation of hexachlorobenzene in rat dams and delays its transfer from rat dams to suckling pups through milk. J Agric Food Chem. 1999; 47(4):1587–1592. 10.1021/jf980831c 10564021
26 Nakashima Y, Ikegami S. High-fat diet enhances the accumulation of hexachlorobenzene (HCB) by pregnant rats during continuous exposure to HCB. J Agric Food Chem. 2003; 51(6):1628–1633. 10.1021/jf020869w 12617596
27 Koss G, Koransky W, Steinbach K. Studies on the toxicology of hexachlorobenzene. II. Identification and determination of metabolites. Arch Toxicol. 1976; 35(2):107–114. 10.1007/BF00372764 947309
28 Koss G, Koransky W, Steinbach K. Studies on the toxicology of hexachlorobenzene. IV. Sulphur-containing metabolites. Arch Toxicol. 1979; 42(1):19–31. 10.1007/BF00351821 454182
29 Smith AG, Francis JE. Evidence for the active renal secretion of S-pentachlorophenyl-N-acetyl-L-cysteine by female rats. Biochem Pharmacol. 1983; 32(24):3797–3801. 10.1016/0006-2952(83)90152-1 6661253
30 To-Figueras J, Barrot C, Rodamilans M, Gomez-Catalan J, Torra M, Brunet M, Sabater F, Corbella J. Accumulation of hexachlorobenzene in humans: A long standing risk. Hum Exp Toxicol. 1995; 14(1):20–23. 10.1177/096032719501400105 7748611
31 Renner G, Nguyen PT. Mechanisms of the reductive denitration of pentachloronitrobenzene (PCNB) and the reductive dechlorination of hexachlorobenzene (HCB). Xenobiotica. 1984; 14(9):705–710. 10.3109/00498258409151468 6516443
32 Renner G, Nguyen PT. Biotransformation of derivatives of the fungicides pentachloronitrobenzene and hexachlorobenzene in mammals. Xenobiotica. 1984; 14(9):693–704. 10.3109/00498258409151467 6516442
33 Rizzardini M, Smith AG. Sex differences in the metabolism of hexachlorobenzene by rats and the development of porphyria in females. Biochem Pharmacol. 1982; 31(22):3543–3548. 10.1016/0006-2952(82)90573-1 7181936
34 Mehendale HM, Fields M, Mathews HB. Metabolism and effects of hexachlorobenzene on hepatic microsomal enzymes in the rat. J Agric Food Chem. 1975; 23(2):261–265. 10.1021/jf60198a042 1133299
35 Yamaguchi Y, Kawano M, Tatsukawa R. Tissue distribution and excretion of hexabromobenzene (HBB) and hexachlorobenzene (HCB) administered to rats. Chemosphere. 1986; 15(4):453–459.10.1016/0045-6535(86)90539-4
36 Yesair DW, Feder PI, Chin AE, Naber SJ, Kuiper-Goodman T, Scott CS, Robinson PE. Development, evaluation and use of a pharmacokinetic model for hexachlorobenzene. IARC Sci Publ. 1986;(77):297–318. 3596717
37 Freeman RA, Rozman KK, Wilson AG. Physiological pharmacokinetic model of hexachlorobenzene in the rat. Health Phys. 1989;57:139–147. 10.1097/00004032-198907001-00017 2606677
38 Lu Y, Lohitnavy M, Reddy MB, Lohitnavy O, Ashley A, Yang RS. An updated physiologically based pharmacokinetic model for hexachlorobenzene: Incorporation of pathophysiological states following partial hepatectomy and hexachlorobenzene treatment. Toxicol Sci. 2006; 91(1):29–41. 10.1093/toxsci/kfj133 16481338
39 Schlummer M, Moser GA, McLachlan MS. Digestive tract absorption of PCDD/Fs, PCBs, and HCB in humans: Mass balances and mechanistic considerations. Toxicol Appl Pharmacol. 1998; 152(1):128–137. 10.1006/taap.1998.8487 9772208
40 Arnot JA, Mackay D, Parkerton TF, Zaleski RT, Warren CS. Multimedia modeling of human exposure to chemical substances: The roles of food web biomagnification and biotransformation. Environ Toxicol Chem. 2010; 29(1):45–55. 10.1002/etc.15 20821418
41 Weistrand C, Noren K. Polychlorinated naphthalenes and other organochlorine contaminants in human adipose and liver tissue. J Toxicol Environ Health A. 1998; 53(4):293–311. 10.1080/009841098159295 9490327
42 Dewailly E, Mulvad G, Pedersen HS, Ayotte P, Demers A, Weber J-P, Hansen JC. Concentration of organochlorines in human brain, liver, and adipose tissue autopsy samples from Greenland. Environ Health Perspect. 1999; 107(10):823–828. 10.1289/ehp.99107823 10504150
43 Minh TB, Watanabe M, Tanabe S, Yamada T, Hata J, Watanabe S. Specific accumulation and elimination kinetics of tris(4-chlorophenyl)methane, tris(4-chlorophenyl)methanol, and other persistent organochlorines in humans from Japan. Environ Health Perspect. 2001; 109(9):927–935. 10.1289/ehp.01109927 11673122
44 Lackmann GM, Goen T, Tolliner U, Schaller KH, Angerer J. PCBs and HCB in serum of full-term German neonates. Lancet. 1996; 348(9033):1035. 10.1016/S0140-6736(05)64967-7 8855887
45 Ando M, Hirano S, Itoh Y. Transfer of hexachlorobenzene (HCB) from mother to new-born baby through placenta and milk. Arch Toxicol. 1985; 56(3):195–200. 10.1007/BF00333426 3977600
46 Sala M, Sunyer J, Otero R, Santiago-Silva M, Ozalla D, Herrero C, To-Figueras J, Kogevinas M, Anto JM, Camps C, et al. Health effects of chronic high exposure to hexachlorobenzene in a general population sample. Arch Environ Health. 1999; 54(2):102–109. 10.1080/00039899909602243 10094287
47 Song S, Ma J, Tian Q, Tong L, Guo X. Hexachlorobenzene in human milk collected from Beijing, China. Chemosphere. 2013; 91(2):145–149. 10.1016/j.chemosphere.2012.12.019 23336922
48 To-Figueras J, Sala M, Otero R, Barrot C, Santiago-Silva M, Rodamilans M, Herrero C, Grimalt J, Sunyer J. Metabolism of hexachlorobenzene in humans: Association between serum levels and urinary metabolites in a highly exposed population. Environ Health Perspect. 1997; 105(1):78–83. 10.1289/ehp.9710578 9074885
49 Koss G, Reuter A, Koransky W. Excretion of metabolites of hexachlorobenzene in the rat and in man. IARC Sci Publ. 1986;(77):261–266. 3596713
50 To-Figueras J, Barrot C, Sala M, Otero R, Silva M, Ozalla MD, Herrero C, Corbella J, Grimalt J, Sunyer J. Excretion of hexachlorobenzene and metabolites in feces in a highly exposed human population. Environ Health Perspect. 2000; 108(7):595–598. 10.1289/ehp.00108595 10903610
51 van Raaij JA, Kaptein E, Visser TJ, van den Berg KJ. Increased glucuronidation of thyroid hormone in hexachlorobenzene-treated rats. Biochem Pharmacol. 1993; 45(3):627–631. 10.1016/0006-2952(93)90136-K 8442763
52 Hahn ME, Goldstein JA, Linko P, Gasiewicz TA. Interaction of hexachlorobenzene with the receptor for 2,3,7,8-tetrachlorodibenzo-p-dioxin in vitro and in vivo. Evidence that hexachlorobenzene is a weak Ah receptor agonist. Arch Biochem Biophys. 1989; 270(1):344–355. 10.1016/0003-9861(89)90037-4 2539049
53 Sinclair PR, Gorman N, Walton HS, Bement WJ, Dalton TP, Sinclair JF, Smith AG, Nebert DW. CYP1A2 is essential in murine uroporphyria caused by hexachlorobenzene and iron. Toxicol Appl Pharmacol. 2000; 162(1):60–67. 10.1006/taap.1999.8832 10631128
54 Kimbrough RD, Linder RE. The toxicity of technical hexachlorobenzene in the Sherman strain rat. A preliminary study. Res Commun Chem Pathol Pharmacol. 1974; 8(4):653–664. 4424873
55 Goldstein JA, Friesen M, Scotti TM, Hickman P, Hass JR, Bergman H. Assessment of the contribution of chlorinated dibenzo-p-dioxins and dibenzofurans to hexachlorobenzene-induced toxicity, porphyria, changes in mixed function oxygenases, and histopathological changes. Toxicol Appl Pharmacol. 1978; 46(3):633–649. 10.1016/0041-008X(78)90309-5 106491
56 Kitchin KT, Linder RE, Scotti TM, Walsh D, Curley AO, Svendsgaard D. Offspring mortality and maternal lung pathology in female rats fed hexachlorobenzene. Toxicology. 1982; 23(1):33–39. 10.1016/0300-483X(82)90039-7 7089983
57 Michielsen CP, Bloksma N, Ultee A, van Mil F, Vos JG. Hexachlorobenzene-induced immunomodulation and skin and lung lesions: A comparison between brown Norway, Lewis, and Wistar rats. Toxicol Appl Pharmacol. 1997; 144(1):12–26. 10.1006/taap.1997.8104 9169065
58 Michielsen CC, van Loveren H, Vos JG. The role of the immune system in hexachlorobenzene-induced toxicity. Environ Health Perspect. 1999; 107 Suppl 5:783–792. 10502545
59 Michielsen CP, Leusink-Muis A, Vos JG, Bloksma N. Hexachlorobenzene-induced eosinophilic and granulomatous lung inflammation is associated with in vivo airways hyperresponsiveness in the Brown Norway rat. Toxicol Appl Pharmacol. 2001; 172(1):11–20. 10.1006/taap.2001.9126 11264018
60 Muller WF, Hobson W, Fuller GB, Knauf W, Coulston F, Korte F. Endocrine effects of chlorinated hydrocarbons in rhesus monkeys. Ecotoxicol Environ Saf. 1978; 2(2):161–172. 10.1016/0147-6513(78)90007-6 103705
61 Foster WG, McMahon A, Villeneuve DC, Jarrell JF. Hexachlorobenzene (HCB) suppresses circulating progesterone concentrations during the luteal phase in the cynomolgus monkey. J Appl Toxicol. 1992; 12(1):13–17. 10.1002/jat.2550120105 1564247
62 Foster WG, McMahon A, Younglai EV, Jarrell JF, Lecavalier P. Alterations in circulating ovarian steroids in hexachlorobenzene-exposed monkeys. Reprod Toxicol. 1995; 9(6):541–548. 10.1016/0890-6238(95)02004-7 8597650
63 Foster WG, Pentick JA, McMahon A, Lecavalier PR. Body distribution and endocrine toxicity of hexachlorobenzene (HCB) in the female rat. J Appl Toxicol. 1993; 13(2):79–83. 10.1002/jat.2550130203 8486915
64 Rozman K, Gorski JR, Rozman P, Parkinson A. Reduced serum thyroid hormone levels in hexachlorobenzene-induced porphyria. Toxicol Lett. 1986; 30(1):71–78. 10.1016/0378-4274(86)90181-5 3952775
65 Visser T, Kaptein E, van Toor H, Van Raaij J, Van den Berg K, Joe C, Van Engelen J, Brouwer A. Glucuronidation of thyroid hormone in rat liver: Effects of in vivo treatment with microsomal enzyme inducers and in vitro assay conditions. Endocrinology. 1993; 133(5):2177–2186. 10.1210/endo.133.5.8404669 8404669
66 Kleiman de Pisarev DL, Ferramola de Sancovich AM, Sancovich HA. Hepatic indices of thyroid status in rats treated with hexachlorobenzene. J Endocrinol Invest. 1995; 18(4):271–276. 10.1007/BF03347812 7560808
67 Smith AG, Dinsdale D, Cabral JR, Wright AL. Goitre and wasting induced in hamsters by hexachlorobenzene. Arch Toxicol. 1987; 60(5):343–349. 10.1007/BF00295753 3662806
68 Vos JG, van Logten MJ, Kreeftenberg JG, Kruizinga W. Hexachlorobenzene-induced stimulation of the humoral immune response in rats. Ann N Y Acad Sci. 1979;320:535–550. 10.1111/j.1749-6632.1979.tb13175.x 378061
69 Can C, Nigogosyan G. Acquired toxic porphyria cutanea tarda due to hexachlorobenzene. Report of 348 cases caused by this fungicide. JAMA. 1963;183:88–91. 14018209
70 Herrero C, Ozalla D, Sala M, Otero R, Santiago-Silva M, Lecha M, To-Figueras J, Deulofeu R, Mascaro JM, Grimalt J, et al. Urinary porphyrin excretion in a human population highly exposed to hexachlorobenzene. Arch Dermatol. 1999; 135(4):400–404. 10.1001/archderm.135.4.400 10206046
71 Sala M, Sunyer J, Herrero C, To-Figueras J, Grimalt J. Association between serum concentrations of hexachlorobenzene and polychlorobiphenyls with thyroid hormone and liver enzymes in a sample of the general population. Occup Environ Med. 2001; 58(3):172–177. 10.1136/oem.58.3.172 11171930
72 Arnold DL, Moodie CA, Charbonneau SM, Grice HC, McGuire PF, Bryce FR, Collins BT, Zawidzka ZZ, Krewski DR, Nera EA. Long-term toxicity of hexachlorobenzene in the rat and the effect of dietary vitamin A. Food Chem Toxicol. 1985; 23(9):779–793. 10.1016/0278-6915(85)90278-9 4043882
73 Grant DL, Phillips WE, Hatina GV. Effect of hexachlorobenzene on reproduction in the rat. Arch Environ Contam Toxicol. 1977; 5(1):207–216. 10.1007/BF02220904 596941
74 Courtney KD, Copeland MF, Robbins A. The effects of pentachloronitrobenzene, hexachlorobenzene, and related compounds on fetal development. Toxicol Appl Pharmacol. 1976; 35(2):239–256. 10.1016/0041-008X(76)90285-4 1265744
75 Andrews JE, Courtney KD. Hexachlorobenzene-induced renal maldevelopment in CD-1 mice and CD rats. IARC Sci Publ. 1986;(77):381–391. 3596728
76 Lilienthal H, Benthe C, Heinzow B, Winneke G. Impairment of schedule-controlled behavior by pre- and postnatal exposure to hexachlorobenzene in rats. Arch Toxicol. 1996; 70(3-4):174–181. 10.1007/s002040050257 8825674
77 Vos JG, van Logten MJ, Kreeftenberg JG, Steerenberg PA, Kruizinga W. Effect of hexachlorobenzene on the immune system of rats following combined pre- and postnatal exposure. Drug Chem Toxicol. 1979; 2(1-2):61–76. 10.3109/01480547908993182 398252
78 Ribas-Fito N, Cardo E, Sala M, Eulalia de Muga M, Mazon C, Verdu A, Kogevinas M, Grimalt JO, Sunyer J. Breastfeeding, exposure to organochlorine compounds, and neurodevelopment in infants. Pediatrics. 2003; 111(5):e580–e585. 10.1542/peds.111.5.e580 12728113
79 Ribas-Fito N, Sala M, Cardo E, Mazon C, De Muga ME, Verdu A, Marco E, Grimalt JO, Sunyer J. Organochlorine compounds and concentrations of thyroid stimulating hormone in newborns. Occup Environ Med. 2003; 60(4):301–303. 10.1136/oem.60.4.301 12660379
80 Ribas-Fito N, Sala M, Cardo E, Mazon C, De Muga ME, Verdu A, Marco E, Grimalt JO, Sunyer J. Association of hexachlorobenzene and other organochlorine compounds with anthropometric measures at birth. Pediatr Res. 2002; 52(2):163–167. 10.1203/00006450-200208000-00006 12149491
81 Smink A, Ribas-Fito N, Garcia R, Torrent M, Mendez MA, Grimalt JO, Sunyer J. Exposure to hexachlorobenzene during pregnancy increases the risk of overweight in children aged 6 years. Acta Paediatr. 2008; 97(10):1465–1469. 10.1111/j.1651-2227.2008.00937.x 18665907
82 Cabral JRP, Shubik P, Mollner T, Raitano F. Carcinogenic activity of hexacholorobenzene in hamsters. Nature. 1977; 269(5628):510. 10.1038/269510a0 198674
83 Cabral JRP, Mollner T, Raitano F, Shubik P. Carcinogenesis of hexachlorobenzene in mice. Int J Cancer. 1979; 23(1):47–51. 10.1002/ijc.2910230110 759379
84 Erturk E, Lambrecht RW, Peters HA, Cripps DJ, Gocmen A, Morris CR, Bryan GT. Oncogenicity of hexachlorobenzene. IARC Sci Publ. 1986;(77):417–423. 3596733
85 National Toxicology Program (NTP). Report on Carcinogens. 14th ed. Research Triangle Park, NC: United States Department of Health and Human Services, Public Health Service, National Institutes of Health; 2016. https://ntp.niehs.nih.gov/whatwestudy/assessments/cancer/roc/index.html?utm_source=direct&utm_medium=prod&utm_campaign=ntpgolinks&utm_term=roc14
86 International Agency for Research on Cancer (IARC). Suppl. 4. Vol. 1-29. Lyon, France: IARC; 1982. (IARC monographs on the evaluation of the carcinogenic risk of chemicals to humans: Chemicals, industrial processes and industries associated with cancer in humans).
87 International Agency for Research on Cancer (IARC). IARC monographs on the evaluation of the carcinogenic risks to humans: Overall evaluations of carcinogenicity: An updating of IARC monographs volumes 1 to 42. Lyon, France: IARC; 1987.
88 U. S. Environmental Protection Agency (USEPA). Integrated Risk Information System: Hexachlorobenzene (CAS# 118-74-1). Washington, DC: U.S. Environmental Protection Agency, Integrated Risk Information System; 2012. https://web.archive.org/web/20120110141038/http://www.epa.gov/iris/subst/0374.htm [Accessed: May 17, 2012]
89 Grimalt JO, Sunyer J, Moreno V, Amaral OC, Sala M, Rosell A, Anto JM, Albaiges J. Risk excess of soft-tissue sarcoma and thyroid cancer in a community exposed to airborne organochlorinated compound mixtures with a high hexachlorobenzene content. Int J Cancer. 1994; 56(2):200–203. 10.1002/ijc.2910560209 8314301
90 International Agency for Research on Cancer (IARC). IARC monographs on the evaluation of carcinogenic risks to humans: Some thyrotropic agents. Vol. 79. Lyon, France: IARC; 2001.
91 Brambilla G, Martelli A. Failure of the standard battery of short-term tests in detecting some rodent and human genotoxic carcinogens. Toxicology. 2004; 196(1-2):1–19. 10.1016/j.tox.2003.11.003 15036752
92 Siekel P, Chalupa I, Beno J, Blasko M, Novotny J, Burian J. A genotoxicological study of hexachlorobenzene and pentachloroanisole. Teratog Carcinog Mutagen. 1991; 11(1):55–60. 10.1002/tcm.1770110107 1677498
93 Haworth S, Lawlor T, Mortelmans K, Speck W, Zeiger E. Salmonella mutagenicity test results for 250 chemicals. Environ Mutagen. 1983; 5 Suppl 1:3–142. 10.1002/em.2860050703 6365529
94 Gopalaswamy UV, Nair CK. DNA binding and mutagenicity of lindane and its metabolites. Bull Environ Contam Toxicol. 1992; 49(2):300–305. 10.1007/BF00191771 1377069
95 Kuroda Y. Genetic and chemical factors affecting chemical mutagenesis in cultured mammalian cells. Basic Life Sci. 1986;39:359–375. 10.1007/978-1-4684-5182-5_31 3767841
96 Ennaceur S, Ridha D, Marcos R. Genotoxicity of the organochlorine pesticides 1, 1-dichloro-2, 2-bis (p-chlorophenyl) ethylene (DDE) and hexachlorobenzene (HCB) in cultured human lymphocytes. Chemosphere. 2008; 71(7):1335–1339. 10.1016/j.chemosphere.2007.11.040 18164367
97 Canonero R, Campart GB, Mattioli F, Robbiano L, Martelli A. Testing of p-dichlorobenzene and hexachlorobenzene for their ability to induce DNA damage and micronucleus formation in primary cultures of rat and human hepatocytes. Mutagenesis. 1997; 12(1):35–40. 10.1093/mutage/12.1.35 9025095
98 Salmon ML, Madanagopal SG, Blando R, Berner J, Williams K. Effects of hexachlorobenzene on embryonic mammalian cells. Toxicol In Vitro. 2002; 16(5):539–548. 10.1016/S0887-2333(02)00054-1 12206821
99 Simon GS, Tardiff RG, Borzelleca JF. Failure of hexachlorobenzene to induce dominant lethal mutations in the rat. Toxicol Appl Pharmacol. 1979; 47(2):415–419. 10.1016/0041-008X(79)90337-5 452032
100 Khera KS. Tetratogenicity and dominant lethal studies on hexachlorobenzene in rats. Food Cosmet Toxicol. 1974; 12(4):471–477. 10.1016/0015-6264(74)90060-1 4459243
101 Gustafson DL, Long ME, Thomas RS, Benjamin SA, Yang RS. Comparative hepatocarcinogenicity of hexachlorobenzene, pentachlorobenzene, 1,2,4,5-tetrachlorobenzene, and 1,4-dichlorobenzene: Application of a medium-term liver focus bioassay and molecular and cellular indices. Toxicol Sci. 2000; 53(2):245–252. 10.1093/toxsci/53.2.245 10696772
102 Linko P, Yeowell HN, Gasiewicz TA, Goldstein JA. Induction of cytochrome P-450 isozymes by hexachlorobenzene in rats and aromatic hydrocarbon (Ah)-responsive mice. J Biochem Toxicol. 1986; 1(2):95–107. 10.1002/jbt.2570010209 2856071
103 Hahn ME, Gasiewicz TA, Linko P, Goldstein JA. The role of the Ah locus in hexachlorobenzene-induced porphyria. Studies in congenic C57BL/6J mice. Biochem J. 1988; 254(1):245–254. 10.1042/bj2540245 2845946
104 Randi AS, Cocca C, Carbone V, Nunez M, Croci M, Gutierrez A, Bergoc R, Kleiman de Pisarev DL. Hexachlorobenzene is a tumor co-carcinogen and induces alterations in insulin-growth factors signaling pathway in the rat mammary gland. Toxicol Sci. 2006; 89(1):83–92. 10.1093/toxsci/kfj023 16237195
105 Pena D, Pontillo C, Garcia MA, Cocca C, Alvarez L, Chiappini F, Bourguignon N, Frahm I, Bergoc R, Kleiman de Pisarev D, et al. Alterations in c-Src/HER1 and estrogen receptor alpha signaling pathways in mammary gland and tumors of hexachlorobenzene-treated rats. Toxicology. 2012; 293(1-3):68–77. 10.1016/j.tox.2011.12.012 22245120
106 National Toxicology Program (NTP). NTP toxicology and carcinogenesis studies of 3,3',4,4',5-pentachlorobiphenyl (PCB 126) (CAS No. 57465-28-8) in female Harlan Sprague-Dawley rats (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2006. Technical Report No. 520.
107 Kociba RJ, Keyes DG, Beyer JE, Carreon RM, Wade CE, Dittenber DA, Kalnins RP, Frauson LE, Park CN, Barnard SD, et al. Results of a two-year chronic toxicity and oncogenicity study of 2,3,7,8-tetrachlorodibenzo-p-dioxin in rats. Toxicol Appl Pharmacol. 1978; 46(2):279–303. 10.1016/0041-008X(78)90075-3 734660
108 National Toxicology Program (NTP). NTP technical report on the toxicology and carcinogenesis studies of 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD) (CAS No. 1746-01-6) in female Harlan Sprague-Dawley rats (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2006. Technical Report No. 521.
109 Boorman GA, Hickman RL, Davis GW, Rhodes LS, White NW, Griffin TA, Mayo J, Hamm TE Jr. Complications of Viral and Mycoplasmal Infections in Rodents to Toxicology Research and Testing. Washington, DC: Hemisphere Publishing Corporation; 1986. Serological titers to murine viruses in 90 day and 2 year studies; p. 11–23.
110 Rao GN, Piegorsch WW, Crawford DD, Edmondson J, Haseman JK. Influence of viral infections on body weight, survival, and tumor prevalence of B6C3F1 (C57BL/6N x C3H/HeN) mice in carcinogenicity studies. Fundam Appl Toxicol. 1989; 13(1):156–164. 10.1016/0272-0590(89)90315-1 2767355
111 Rao GN, Haseman JK, Edmondson J. Influence of viral infections on body weight, survival, and tumor prevalence in Fischer 344/NCr rats on two-year studies. Lab Anim Sci. 1989; 39(5):389–393. 2554057
112 Van den Berg M, Birnbaum LS, Denison M, De Vito M, Farland W, Feeley M, Fiedler H, Hakansson H, Hanberg A, Haws L, et al. The 2005 World Health Organization reevaluation of human and mammalian toxic equivalency factors for dioxins and dioxin-like compounds. Toxicol Sci. 2006; 93(2):223–241. 10.1093/toxsci/kfl055 16829543
113 Lambrecht RW, Erturk E, Grunden EE, Peters HA, Morns CR, Bryan GT. Hepatocarcinogenicity of chronically administered hexachlorobenzene in rats. Fed Proc. 1983;42:786.
114 Lambrecht RW, Erturk E, Grunden EE, Peters HA, Morns CR, Bryan GT. Renal tumors in rats chronically exposed to hexachlorobenzene. Proc Am Assoc Cancer Res. 1983;24:59.
115 Pearce RE, McIntyre CJ, Madan A, Sanzgiri U, Draper AJ, Bullock PL, Cook DC, Burton LA, Latham J, Nevins C, et al. Effects of freezing, thawing, and storing human liver microsomes on cytochrome P450 activity. Arch Biochem Biophys. 1996; 331(2):145–169. 10.1006/abbi.1996.0294 8660694
116 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
117 Boorman GA, Haseman JK, Waters MD, Hardisty JF, Sills RC. Quality review procedures necessary for rodent pathology databases and toxicogenomic studies: The National Toxicology Program experience. Toxicol Pathol. 2002; 30(1):88–92. 10.1080/01926230252824752 11890481
118 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
119 Armitage P. Statistical methods in medical research. Oxford: Blackwell; 1971.
120 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121.10.1080/01621459.1955.10501294
121 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
122 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
123 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
124 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
125 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252.10.1080/00401706.1964.10490181
126 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41:133–145.10.1093/biomet/41.1-2.133
127 Dixon WJ, Massey FJ Jr. Introduction to statistical analysis. 2nd ed. New York, NY: McGraw-Hill Book Company; 1957. p. 276–278, 412.
128 Code of Federal Regulations (CFR). 21:Part 58.
129 National Toxicology Program (NTP). TOX-77: Toxicity report tables & curves: Pathology tables, survival and growth curves from NTP short-term and toxicokinetics studies. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2020. 10.22427/NTP-DATA-TOX-77
130 Long PH, Herbert RA, Nyska A. Hexachlorobenzene-induced incisor degeneration in Sprague-Dawley rats. Toxicol Pathol. 2004; 32(1):35–40. 10.1080/01926230490260871 14713546
131 DeVito MJ, Diliberto JJ, Ross DG, Menache MG, Birnbaum LS. Dose-response relationships for polyhalogenated dioxins and dibenzofurans following subchronic treatment in mice. I. CYP1A1 and CYP1A2 enzyme activity in liver, lung, and skin. Toxicol Appl Pharmacol. 1997; 147(2):267–280. 10.1006/taap.1997.8261 9439722
132 Kuiper-Goodman T, Grant DL, Moodie CA, Korsrud GO, Munro IC. Subacute toxicity of hexachlorobenzene in the rat. Toxicol Appl Pharmacol. 1977; 40(3):529–549. 10.1016/0041-008X(77)90078-3 882985
133 Smith AG, Cabral JR. Liver-cell tumours in rats fed hexachlorobenzene. Cancer Lett. 1980; 11(2):169–172. 10.1016/0304-3835(80)90108-1 7459845
134 Schielen P, Den Besten C, Vos JG, Van Bladeren PJ, Seinen W, Bloksma N. Immune effects of hexachlorobenzene in the rat: Role of metabolism in a 13-week feeding study. Toxicol Appl Pharmacol. 1995; 131(1):37–43. 10.1006/taap.1995.1044 7878676
135 Stockinger B, Meglio PD, Gialitakis M, Duarte JH. The aryl hydrocarbon receptor: Multitasking in the immune system. Annu Rev Immunol. 2014; 32(1):403–432. 10.1146/annurev-immunol-032713-120245 24655296
136 Miret N, Rico-Leo E, Pontillo C, Zotta E, Fernandez-Salguero P, Randi A. A dioxin-like compound induces hyperplasia and branching morphogenesis in mouse mammary gland, through alterations in TGF-beta1 and aryl hydrocarbon receptor signaling. Toxicol Appl Pharmacol. 2017;334:192–206. 10.1016/j.taap.2017.09.012 28923513
137 Miret NV, Pontillo CA, Zarate LV, Kleiman de Pisarev D, Cocca C, Randi AS. Impact of endocrine disruptor hexachlorobenzene on the mammary gland and breast cancer: The story thus far. Environ Res. 2019;173:330–341. 10.1016/j.envres.2019.03.054 30951959
138 Kiukkonen A, Viluksela M, Sahlberg C, Alaluusua S, Tuomisto JT, Tuomisto J, Lukinmaa PL. Response of the incisor tooth to 2,3,7,8-tetrachlorodibenzo-p-dioxin in a dioxin-resistant and a dioxin-sensitive rat strain. Toxicol Sci. 2002; 69(2):482–489. 10.1093/toxsci/69.2.482 12377997
139 Sahlberg C, Pohjanvirta R, Gao Y, Alaluusua S, Tuomisto J, Lukinmaa PL. Expression of the mediators of dioxin toxicity, aryl hydrocarbon receptor (AHR) and the AHR nuclear translocator (ARNT), is developmentally regulated in mouse teeth. Int J Dev Biol. 2002; 46(3):295–300. 12068950
140 Schmidt CK, Hoegberg P, Fletcher N, Nilsson CB, Trossvik C, Håkansson H, Nau H. 2,3,7,8-Tetrachlorodibenzo-p-dioxin (TCDD) alters the endogenous metabolism of all-trans-retinoic acid in the rat. Arch Toxicol. 2003; 77(7):371–383. 10.1007/s00204-003-0457-8 12851740
141 Nilsson CB, Håkansson H. The retinoid signaling system— A target in dioxin toxicity. Crit Rev Toxicol. 2002; 32(3):211–232. 10.1080/20024091064228 12071573
142 Alaluusua S, Lukinmaa PL, Pohjanvirta R, Unkila M, Tuomisto J. Exposure to 2, 3, 7, 8-tetrachlorodibenzo-para-dioxin leads to defective dentin formation and pulpal perforation in rat incisor tooth. Toxicology. 1993; 81(1):1–13. 10.1016/0300-483X(93)90152-I 8367879
143 Alaluusua S, Lukinmaa PL, Koskimies M, Pirinen S, Holtta P, Kallio M, Holttinen T, Salmenpera L. Developmental dental defects associated with long breast feeding. Eur J Oral Sci. 1996; 104(5-6):493–497. 10.1111/j.1600-0722.1996.tb00131.x 9021315
144 Alaluusua S, Lukinmaa PL, Torppa J, Tuomisto J, Vartiainen T. Developing teeth as biomarker of dioxin exposure. Lancet. 1999; 353(9148):206. 10.1016/S0140-6736(05)77214-7 9923879
145 Holtta P, Kiviranta H, Leppaniemi A, Vartiainen T, Lukinmaa PL, Alaluusua S. Developmental dental defects in children who reside by a river polluted by dioxins and furans. Arch Environ Health. 2001; 56(6):522–528. 10.1080/00039890109602901 11958552
146 Kattainen H, Tuukkanen J, Simanainen U, Tuomisto JT, Kovero O, Lukinmaa PL, Alaluusua S, Tuomisto J, Viluksela M. In utero/lactational 2,3,7,8-tetrachlorodibenzo-p-dioxin exposure impairs molar tooth development in rats. Toxicol Appl Pharmacol. 2001; 174(3):216–224. 10.1006/taap.2001.9216 11485382
147 Lukinmaa PL, Sahlberg C, Leppaniemi A, Partanen A-M, Kovero O, Pohjanvirta R, Tuomisto J, Alaluusua S. Arrest of rat molar tooth development by lactational exposure to 2, 3, 7, 8-tetrachlorodibenzo-p-dioxin. Toxicol Appl Pharmacol. 2001; 173(1):38–47. 10.1006/taap.2001.9155 11350213
148 van Raaij JA, Frijters CM, van den Berg KJ. Hexachlorobenzene-induced hypothyroidism. Involvement of different mechanisms by parent compound and metabolite. Biochem Pharmacol. 1993; 46(8):1385–1391. 10.1016/0006-2952(93)90103-4 8240387
149 Chiappini F, Alvarez L, Lux-Lantos V, Randi AS, Kleiman de Pisarev DL. Hexachlorobenzene triggers apoptosis in rat thyroid follicular cells. Toxicol Sci. 2009; 108(2):301–310. 10.1093/toxsci/kfp016 19182106
150 Den Besten C, Bennik MHJ, Bruggeman I, Schielen P, Kuper F, Brouwer A, Koeman JH, Vos JG, Vanbladeren PJ. The role of oxidative metabolism in hexachlorobenzene-induced porphyria and thyroid hormone homeostasis: A comparison with pentachlorobenzene in a 13-week feeding study. Toxicol Appl Pharmacol. 1993; 119(2):181–194. 10.1006/taap.1993.1059 8480328
151 Ãlvarez L, Hernandez S, Martinez-de-Mena R, Kolliker-Frers R, Obregon MJ, De Pisarev DLK. The role of type I and type II 5′ deiodinases on hexachlorobenzene-induced alteration of the hormonal thyroid status. Toxicology. 2005; 207(3):349–362. 10.1016/j.tox.2004.10.006 15664263
152 Vanbirgelen AP, Vanderkolk J, Fase KM, Bol I, Poiger H, Vandenberg M, Brouwer A. Toxic potency of 2,3,3′,4,4′,5-hexachlorobiphenyl relative to and in combination with 2,3,7,8-tetrachlorodibenzo-p-dioxin in a subchronic feeding study in the rat. Toxicol Appl Pharmacol. 1994; 126(2):202–213. 10.1006/taap.1994.1109 8209374
153 Schwarz M, Buchmann A, Stinchcombe S, Kalkuhl A, Bock K. Ah receptor ligands and tumor promotion: Survival of neoplastic cells. Toxicol Lett. 2000;112-113:69–77. 10.1016/S0378-4274(99)00247-7 10720714
154 Elcombe CR, Peffer RC, Wolf DC, Bailey J, Bars R, Bell D, Cattley RC, Ferguson SS, Geter D, Goetz A, et al. Mode of action and human relevance analysis for nuclear receptor-mediated liver toxicity: A case study with phenobarbital as a model constitutive androstane receptor (CAR) activator. Crit Rev Toxicol. 2014; 44(1):64–82. 10.3109/10408444.2013.835786 24180433
155 Randi AS, Sanchez MS, Alvarez L, Cardozo J, Pontillo C, Kleiman de Pisarev DL. Hexachlorobenzene triggers AhR translocation to the nucleus, c-Src activation and EGFR transactivation in rat liver. Toxicol Lett. 2008; 177(2):116–122. 10.1016/j.toxlet.2008.01.003 18295415
156 de Tomaso Portaz AC, Caimi GR, Sánchez M, Chiappini F, Randi AS, de Pisarev DLK, Alvarez L. Hexachlorobenzene induces cell proliferation, and aryl hydrocarbon receptor expression (AhR) in rat liver preneoplastic foci, and in the human hepatoma cell line HepG2. AhR is a mediator of ERK1/2 signaling, and cell cycle regulation in HCB-treated HepG2 cells. Toxicology. 2015;336:36–47. 10.1016/j.tox.2015.07.013 26219504
157 Garcia MA, Pena D, Ãlvarez L, Cocca C, Pontillo C, Bergoc R, de Pisarev DK, Randi A. Hexachlorobenzene induces cell proliferation and IGF-I signaling pathway in an estrogen receptor alpha-dependent manner in MCF-7 breast cancer cell line. Toxicol Lett. 2010; 192(2):195–205. 10.1016/j.toxlet.2009.10.026 19879930
158 Kazantseva YA, Pustylnyak YA, Pustylnyak VO. Role of nuclear constitutive androstane receptor in regulation of hepatocyte proliferation and hepatocarcinogenesis. Biochemistry (Mosc). 2016; 81(4):338–347. 10.1134/s0006297916040040 27293091
159 Kolaya KL, Stevenson DE, Walborg EF Jr, Klaunig JE. Dose dependence of phenobarbital promotion of preneoplastic hepatic lesions in F344 rats and B6C3F1 mice: Effects on DNA synthesis and apoptosis. Carcinogenesis. 1996; 17(5):947–954. 10.1093/carcin/17.5.947 8640942
160 Goldstein JA, Linko P, Hahn ME, Gasiewicz TA, Yeowell HN. Structure-activity relationships of chlorinated benzenes as inducers of hepatic cytochrome P-450 isozymes in the rat. IARC Sci Publ. 1986;(77):519–526. 3596751
161 Schmidt JV, Su GH, Reddy JK, Simon MC, Bradfield CA. Characterization of a murine Ahr null allele: Involvement of the Ah receptor in hepatic growth and development. Proc Natl Acad Sci USA. 1996; 93(13):6731–6736. 10.1073/pnas.93.13.6731 8692887
162 Paolini M, Mesirca R, Pozzetti L, Sapone A, Cantelli-Forti G. Induction of CYP2B1 mediated pentoxyresorufin O-dealkylase activity in different species, sex and tissue by prototype 2B1-inducers. Chem Biol Interact. 1995; 95(1-2):127–139. 10.1016/0009-2797(94)03352-8 7697745
163 Ingebrigtsen K, Nafstad I. Distribution and elimination of 14C-hexachlorobenzene after single oral exposure in the male rat. Acta Pharmacol Toxicol (Copenh). 1983; 52(4):254–260. 10.1111/j.1600-0773.1983.tb01096.x 6869020
164 Iatropoulos MJ, Milling A, Müller WF, Nohynek G, Rozman K, Coulston F, Korte F. Absorption, transport and organotropism of dichlorobiphenyl (DCB), Dieldrin, and hexachlorobenzene (HCB) in rats. Environ Res. 1975; 10(3):384–389. 10.1016/0013-9351(75)90033-X 1213019
165 Muller WF, Scheunert I, Rozman K, Kogel W, Freitag D, Richter E, Coulston F, Korte F. Comparative metabolism of hexachlorobenzene and pentachloronitrobenzene in plants, rats, and rhesus monkeys. Ecotoxicol Environ Saf. 1978; 2(3-4):437–445. 10.1016/S0147-6513(78)80017-7 109270
166 Morita M, Oishi S. Clearance and tissue distribution of hexachlorobenzene in rats. Bull Environ Contam Toxicol. 1975; 14(3):313–318. 10.1007/BF01685643 1174745
167 Viluksela M, Raasmaja A, Lebofsky M, Stahl BU, Rozman KK. Tissue-specific effects of 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD) on the activity of 5′-deiodinases I and II in rats. Toxicol Lett. 2004; 147(2):133–142. 10.1016/j.toxlet.2003.10.025 14757317
168 Giribaldi L, Chiappini F, Pontillo C, Randi AS, de Pisarev DLK, Alvarez L. Hexachlorobenzene induces deregulation of cellular growth in rat liver. Toxicology. 2011; 289(1):19–27. 10.1016/j.tox.2011.07.004 21787832
169 Bock KW, Kohle C. Ah receptor-and TCDD-mediated liver tumor promotion: Clonal selection and expansion of cells evading growth arrest and apoptosis. Biochem Pharmacol. 2005; 69(10):1403–1408. 10.1016/j.bcp.2005.02.004 15857604
170 Pouchert CJ. 1985. The Aldrich Library of FT-IR Spectra: Vol. 1, p. 1016, spectrum B. Milwaukee, WI: Aldrich Chemical Company, Inc.