# Discussion

Despite the cessation of its use and production in many parts of the world, hexachlorobenzene (HCB) remains highly persistent in the environment, and chronic, low-dose exposure to HCB in humans continues. Its structural resemblance to 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD), ability to activate the aryl hydrocarbon (Ah) receptor, TCDD-like toxicities, and bioaccumulative nature suggest HCB be included in the toxic equivalency factor (TEF) methodology (outlined in Van den Berg et al.^112^). Consequently, the National Toxicology Program (NTP) conducted this study to determine relative potency values for HCB, measuring a variety of toxicological and biochemical endpoints that also were measured at the 3-month time point in a TCDD 2-year bioassay.^108^ Additional animals were allocated to assess the half-life of HCB in blood and to examine HCB elimination in tissues after repeated exposures to address a knowledge gap in pharmacokinetics in this strain of rat.

## Core Study

HCB had no significant effect on survival. Mean body weight was not significantly changed in most dosed groups, which is consistent with many other subchronic studies of HCB at similar doses.^3^ Some studies have shown decreased body weight with HCB exposure; however, these decreases were generally <20% from control body weight.^132,133^ Rats in the highest dose group, 25 mg HCB/kg body weight/day (mg/kg/day), had significantly increased mean body weight compared to the vehicle control group at study termination. Slight increases in body weight also have also been observed in another subchronic study of HCB in Wistar rats, although those increases occurred at higher doses (900 mg/kg/day).^57^

At higher doses of HCB, weights of the spleen (3, 10, and 25 mg/kg/day), liver (10 and 25 mg/kg/day), lung (25 mg/kg/day), and kidney (25 mg/kg/day) were significantly increased compared to those of the vehicle control group. Increases in liver and spleen weights were correlated with significant pathological changes, such as increased incidences of hepatocyte hypertrophy and lymphoid hyperplasia of the spleen in the 10 and 25 mg/kg/day groups. Enlargement of the liver and spleen has been observed in previous studies of HCB.^57,132,134^ The significant increase in kidney weight in the 25 mg/kg/day group was not associated with any significant morphological changes.

Increased incidences of chronic inflammation occurred in the lung and skin. Inflammation in the lung and skin has also been observed in a 4-week dietary HCB exposure study.^57^ Female rats from multiple strains developed epidermal hyperplasia, activated venule endothelium, and inflammatory infiltrates in the skin and high endothelial-like venules, perivascular infiltrate, and accumulation of macrophages in the lung. Serum immunoglobulins as indicators of immunomodulation correlated with skin but not lung lesions. These data suggest that HCB induces a chronic inflammatory reaction and that HCB-induced skin and lung lesions have different etiologies.^57^ Furthermore, inflammatory effects of HCB appear thymus-independent.^58^ Thus, the observed thymic atrophy at 25 mg/kg/day, which did not correspond with decreased thymic weight, might not be related to the skin or lung inflammatory lesions. TCDD has been reported to be immunomodulatory, particularly in barrier tissues like the skin and lung,^135^ though in a 2-year study in rats, TCDD exposure was not associated with increased incidences of skin or lung inflammation.^108^

The incidence of mammary gland hyperplasia was increased in the 25 mg/kg/day group compared to the vehicle control group. Mammary gland hyperplasia has been observed in other rat studies evaluating HCB exposure. Sprague Dawley rats given 100 mg/kg HCB by gavage for 45 days and initiated with N-nitroso-N-methylurea had higher incidence of preneoplastic lesions in the mammary gland.^104^ Increased mammary gland hyperplasia also was observed in C57BL6/N mice treated with 3 mg/kg HCB via intraperitoneal injection for 21 days.^136^ These mammary gland effects of HCB have been proposed as being due to activation of the Ah receptor, which influences insulin growth factor, transforming growth factor beta 1, and estrogen receptor signaling pathways.^137^

Maxillary incisor degeneration was observed in animals administered HCB at doses of ≥1 mg/kg/day. The morphology and distribution of HCB-induced incisor lesions in rats are consistent with injury to a selective population of preodontoblasts and support a direct cytotoxic mechanism of action.^130^ Dioxins can interfere with the development of incisors and molars and can alter mesenchymal and epithelial dental tissues.^138^ The mechanism by which dioxins cause dental injury is thought to be mediated through the Ah receptor together with the Ah receptor nuclear translocator protein.^139^ Others have suggested a role for vitamin A in mediating the toxic effects of TCDD because TCDD is known to interfere with vitamin A metabolism.^140,141^ The dentin effects of TCDD are similar to those observed with vitamin A deficiency.^142^ Decreased regional blood flow also has been suggested as a possible mechanism by which dioxins injure dental tissues.^138^ Dentin niches, which were observed in this study, however, are not reported features of TCDD toxicity.^138,139,142-147^

At study termination, serum total triiodothyronine (T_3_) was decreased in the 25 mg/kg/day group, and both free and total thyroxine (T_4_) were decreased in the 10 and 25 mg/kg/day groups. These observed changes in thyroid hormones were not accompanied by a compensatory increase in thyroid stimulating hormone (TSH) or changes in thyroid gland pathology (e.g., hyperplasia). Other rat studies have shown similar decreases in total T_4_, with or without decreases in total T_3_ or increases in TSH.^64,66,148-151^ Evaluation of another time point would provide further insight into mechanisms of HCB-associated thyroid impairment. Studies suggest that decreases in circulating total T_4_ could be due to increased glucuronidation (i.e., increased uridine diphosphoglucuronosyl transferase) leading to increased biliary excretion of T_4_.^51,151^ Alterations in thyroid hormone homeostasis are well-described with TCDD exposure and are purported to undergo a similar extrathyroidal mechanism similar to that of HCB.^152^ In rats administered 1,000 mg/kg HCB via stomach tube, increases in total body 5′-deiodinase type I (which converts T_4_ to T_3_) was considered a major contributor to the maintenance of serum T_3_ levels.^151^ Moreover, metabolites of HCB might contribute to alterations in total and free T_4_ concentrations by competitively binding to thyroid transport proteins.^148^

A slight, nonsignificant increase in hepatic cell proliferation occurred with 10 and 25 mg/kg/day HCB. Hepatic cell proliferation is often studied to understand the tumor promotion potential of a chemical. Because TCDD and related congeners (like HCB) are not direct genotoxic agents, their primary mode of carcinogenic action is presumed to be via growth dysregulation mediated through the Ah receptor, either by increasing net growth or decreasing cell death (reviewed in Schwarz et al.^153^). Though the increase in cell proliferation due to Ah receptor activation typically occurs in the first week of exposure,^154^ the continued presence of higher cell proliferation in HCB-dosed animals may be due to a higher number of proliferating hepatocytes from earlier exposures and/or a regenerative response to liver injury. HCB exposure has been observed to produce liver tumors in three species (mice, rats, and hamsters).^1^ This effect is mediated, in part, through the Ah receptor because Ah receptor-dependent cell proliferation pathways have been shown to be activated following HCB exposure.^155-157^ Other mechanisms are likely involved in HCB carcinogenicity, however, as demonstrated by the large induction of hepatic pentoxyresorufin-O-deethylase (PROD) activity, which is likely due to constitutive androstane receptor (CAR) activation. CAR is known to participate in rodent hepatocarcinogenesis.^158^ In fact, in rodents, the CAR-activator phenobarbital increased replicative DNA synthesis in regions of altered hepatic foci produced by initiation with diethylnitrosamine,^159^ indicating the role of CAR in tumor promotion.

Hepatic 7-ethoxyresorufin-O-deethylase (EROD), acetanilide-4-hydroxylase (A4H), and PROD activity was significantly increased in most groups of rats administered HCB, suggesting that CYP1A1, CYP1A2, CYP2B1, and CYP2B2 expression was induced by HCB. Increases in pulmonary EROD activity were observed only at 25 mg/kg/day. These findings are consistent with previous studies showing induction of Cyp genes by HCB.^64,102,160^ Extensive studies show that TCDD induces CYP1A1 expression through the Ah receptor.^161^ PROD activity is often associated with induction of phenobarbital-inducible CYP enzymes such as CYP2B1 and CYP2B2. Though this may suggest broader activity of HCB, PROD activity was also increased with TCDD exposure and thus might not be entirely specific to CYP2B enzymes, reflecting some CYP1A activity. Indeed, CYP1A1 has been found to also dealkylate pentoxyresorufin.^162^ Additionally, in this study, tissues were frozen prior to evaluation of microsomal activity, which may have resulted in a loss of activity^115^ and an incomplete picture of HCB-induced microsomal enzymes.

Concentrations of HCB in blood and tissues increased in proportion to dose. The distribution pattern of HCB among the tissues in this study is similar to that observed in single administration studies in which the concentration of HCB in the blood and liver was higher or equivalent to that in the lung but lower than concentrations in adipose tissue.^34,35,163-166^ Accumulation of HCB in adipose tissue is likely due to the lipophilicity of HCB. The ratios of tissue to blood HCB concentrations after repeated dosing in this study were similar to those observed in the single administration toxicokinetic study (Appendix D). The decreasing difference between tissue and blood HCB concentration with increasing dose suggests saturation of HCB accumulation after repeated exposure to high doses.

## Relative Potency Factor Determination

The generation of relative potency factors (RPFs) of HCB compared with TCDD was deemed inappropriate due to significant differences in the dose-response relationships for Ah receptor-mediated activity. The maximal response for HCB was not reached in many of the endpoints, and the available data did not suggest parallel dose-response curves with TCDD. Although exposure to HCB yields some of the same toxicities as TCDD exposure (e.g., hepatic porphyria, altered thyroid hormone, and tumorigenicity), the lack of parallel dose-response curves and the differences in directionality and maximum effect in some endpoints suggest that the mechanisms of action of HCB differ from those of TCDD. For example, whereas HCB has been found to alter 5’-deiodinase activities in the liver and thyroid gland, changes in 5’-deiodinase likely do not significantly influence circulating levels of T_4_ or T_3_ in TCDD-exposed rats.^167^ HCB has been found to induce apoptosis in rat hepatocytes and thyroid follicular cells,^149,168^ unlike TCDD, which tends to suppress apoptosis.^153,169^

## Elimination Study

HCB was retained in the adipose tissue at 8 and 16 weeks after cessation of exposure. Evidenced by approximately equivalent blood and tissue HCB concentrations, minimal retention was observed in the lung and liver. The toxicological effects of HCB exposure, such as increased liver weight and elevated hepatic EROD activity, were still present at both postexposure time points in the 25 mg/kg/day dose group, but the effects were of a lower magnitude; there were no significant effects on those endpoints in the 0.03 mg/kg/day dose group at later time points. Taken together, HCB is retained primarily in the adipose tissue and continues to influence biological processes, even up to 16 weeks after cessation of exposure.

The half-life of HCB after repeated administration was assessed in the blood because these kinetic parameters have not been determined for female Sprague Dawley rats. In the present study, the half-life of HCB in blood of female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats was estimated to be 53 (0.03 mg/kg/day) and 48 (25 mg/kg/day) days. The half-life of HCB in blood of female Sprague Dawley rats after a single administration of 0.03 and 30 mg/kg was estimated to be 23 and 11 days, respectively (Appendix D). These data suggest slower HCB elimination following repeated exposures.

Under the conditions of this 3-month gavage study, oral administration of HCB in female Sprague Dawley rats resulted in dose-related lesions in the liver, lung, spleen, mammary gland, skin, thymus, and teeth. HCB administration decreased total T_3_, free T_4_, and total T_4_; there were no compensatory increases in TSH and no thyroid histological changes observed. Consistent with literature indicating that HCB acts through other mechanisms in addition to activation of the Ah receptor, these data indicate that HCB should not be included in the TEF methodology.