# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TOX-77.^129^

## Core Study

One 0.03 mg HCB/kg body weight/day (mg/kg/day) core study rat died during week 13 of the study; all other rats survived to study termination (Table 2; [underlined: Appendix F]). The mean body weight gains of the 10 and 25 mg/kg/day groups and the final mean body weight of the 25 mg/kg/day group were significantly increased compared to the vehicle control group (Table 2; Figure 2; [underlined: Appendix F]). No chemical-related clinical findings were observed.

Table 2 Summary of Survival and Mean Body Weights for Core Study Female Rats in the Threemonth Gavage Study of Hexachlorobenzene^a,b^

Dose (mg/kg/day) | Survival^c^ | Initial Body Weight (g) | Final Body Weight (g)^d^ | Change in Body Weight (g) | Final Weight Relative to Controls (%)
0 | 10/10 | 181.1 ± 2.4 | 264.3 ± 4.6** | 83.3 ± 3.3** | –
0.03 | 9/10^e^ | 183.5 ± 1.8 | 259.7 ± 5.9 | 76.9 ± 4.4 | −1.77
0.1 | 10/10 | 181.0 ± 2.5 | 253.8 ± 3.1 | 72.8 ± 3.9 | −4.00
0.3 | 10/10 | 182.8 ± 1.9 | 257.3 ± 5.2 | 74.5 ± 4.2 | −2.66
1 | 10/10 | 183.8 ± 2.5 | 264.8 ± 2.6 | 81.0 ± 2.8 | 0.16
3 | 10/10 | 183.4 ± 2.6 | 273.2 ± 4.7 | 89.8 ± 4.0 | 3.34
10 | 10/10 | 179.9 ± 2.3 | 278.3 ± 7.5 | 98.4 ± 6.2* | 5.28
25 | 10/10 | 181.3 ± 1.6 | 293.6 ± 6.0** | 112.3 ± 5.4** | 11.08

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Number of animals surviving at 3 months/number initially in group.

^d^ Body weight at necropsy.

^e^ Week of death: 13.

Figure 2

Growth Curves for Core Study Female Rats Administered Hexachlorobenzene by Gavage for Three Months

At study termination, absolute and relative spleen weights of the 3, 10, and 25 mg/kg/day groups, liver weights of the 10 and 25 mg/kg/day groups, and lung weights of the 25 mg/kg/day group were significantly increased compared to those of the vehicle control group; the absolute kidney weight of the 25 mg/kg/day group was also significantly increased (Table 3; [underlined: Appendix F]). No significant differences in ovary, thymus, or thyroid gland weight occurred in any dosed group compared to the vehicle control group.

Table 3 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Core Study Female Rats in the Three-month Gavage Study of Hexachlorobenzene^a,b^

| 0 mg/kg/day | 0.03 mg/kg/day | 0.1 mg/kg/day | 0.3 mg/kg/day | 1 mg/kg/day | 3 mg/kg/day | 10 mg/kg/day | 25 mg/kg/day
n | 10 | 9 | 10 | 10 | 10 | 10 | 10 | 10
Necropsy Body Wt. (g) | 264.3 ± 4.6** | 259.7 ± 5.9 | 253.8 ± 3.1 | 257.3 ± 5.2 | 264.8 ± 2.6 | 273.2 ± 4.7 | 278.3 ± 7.5 | 293.6 ± 6.0**
Right Kidney
Absolute (g) | 0.73 ± 0.02** | 0.74 ± 0.02 | 0.72 ± 0.01 | 0.74 ± 0.03 | 0.74 ± 0.01 | 0.75 ± 0.02 | 0.78 ± 0.02 | 0.86 ± 0.02**
Relative (mg/g) | 2.75 ± 0.06 | 2.84 ± 0.06 | 2.82 ± 0.02 | 2.88 ± 0.07 | 2.80 ± 0.04 | 2.75 ± 0.06 | 2.80 ± 0.05 | 2.92 ± 0.06
Liver
Absolute (g) | 8.32 ± 0.21** | 7.64 ± 0.25 | 7.75 ± 0.20 | 7.91 ± 0.30 | 8.22 ± 0.20 | 8.89 ± 0.21 | 10.28 ± 0.47** | 12.53 ± 0.41**
Relative (mg/g) | 31.47 ± 0.54** | 29.40 ± 0.54 | 30.51 ± 0.64 | 30.68 ± 0.63 | 31.01 ± 0.59 | 32.54 ± 0.58 | 36.83 ± 0.88** | 42.82 ± 1.68**
Lung
Absolute (g) | 1.58 ± 0.08** | 1.54 ± 0.05 | 1.54 ± 0.03 | 1.56 ± 0.06 | 1.56 ± 0.07 | 1.70 ± 0.07 | 1.70 ± 0.08 | 2.08 ± 0.08**
Relative (mg/g) | 5.95 ± 0.22** | 5.93 ± 0.13 | 6.09 ± 0.12 | 6.05 ± 0.18 | 5.90 ± 0.26 | 6.20 ± 0.20 | 6.09 ± 0.22 | 7.10 ± 0.22**
Spleen
Absolute (mg) | 576 ± 20** | 587 ± 14 | 565 ± 20 | 590 ± 31 | 566 ± 12 | 666 ± 19** | 689 ± 26** | 952 ± 29**
Relative (mg/g) | 2.17 ± 0.05** | 2.27 ± 0.05 | 2.23 ± 0.07 | 2.28 ± 0.09 | 2.14 ± 0.04 | 2.44 ± 0.06** | 2.47 ± 0.06** | 3.24 ± 0.09**

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

Total triiodothyronine (T_3_) was significantly decreased by 1.7-fold in the 25 mg/kg/day group compared to the vehicle control group (Table 4; [underlined: Appendix F]). Total thyroxine (T_4_) and free T_4_ were significantly decreased in the 10 and 25 mg/kg/day groups compared to the vehicle control group. No significant differences in thyroid stimulating hormone (TSH) were observed in any dosed group compared to the vehicle control group.

Table 4 Summary of Serum Concentrations of Thyroid Hormones for Core Study Female Rats in the Three-month Gavage Study of Hexachlorobenzene^a,b^

| 0 mg/kg/day | 0.03 mg/kg/day | 0.1 mg/kg/day | 0.3 mg/kg/day | 1 mg/kg/day | 3 mg/kg/day | 10 mg/kg/day | 25 mg/kg/day
n | 10 | 9 | 10 | 10 | 10 | 10 | 10 | 10
T_3_ (ng/dL) | 155.000 ± 12.189** | 138.867 ± 8.791 | 132.140 ± 9.665 | 157.130 ± 11.718 | 130.540 ± 10.972 | 144.150 ± 13.213 | 131.670 ± 4.759 | 93.630 ± 6.367**
Total T_4_ (μg/dL) | 5.43 ± 0.31** | 6.73 ± 0.38 | 5.70 ± 0.35 | 5.99 ± 0.42 | 5.44 ± 0.31 | 4.77 ± 0.38 | 2.03 ± 0.36** | 0.04 ± 0.04**
Free T_4_ (ng/dL) | 2.983 ± 0.107** | 3.35 ± 0.200 | 3.046 ± 0.321 | 2.891 ± 0.260 | 2.470 ± 0.152 | 2.430 ± 0.205 | 1.455 ± 0.124** | 0.536 ± 0.039**
TSH (ng/mL) | 10.450 ± 0.864 | 10.200 ± 1.018 | 11.430 ± 1.183 | 10.890 ± 0.569 | 11.710 ± 1.361 | 11.230 ± 0.604 | 10.550 ± 1.163 | 10.680 ± 1.069

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

T_3_ = triiodothyronine; T_4_ = thyroxine; TSH = thyroid stimulating hormone.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

No significant pairwise differences in hepatocyte proliferation were observed between dosed groups and the vehicle control group (Table 5; [underlined: Appendix F]). A significant positive trend was observed, and the labeling index in the 10 and 25 mg/kg/day groups was approximately twofold higher than that in the vehicle control group.

Table 5 Summary of Hepatic Cell Proliferation Data for Core Study Female Rats in the Three-month Gavage Study of Hexachlorobenzene^a,b^

| 0 mg/kg/day | 0.03 mg/kg/day | 0.1 mg/kg/day | 0.3 mg/kg/day | 1 mg/kg/day | 3 mg/kg/day | 10 mg/kg/day | 25 mg/kg/day
n | 10 | 9 | 10 | 10 | 10 | 10 | 10 | 10
Total Cells Counted | 2,202 ± 39 | 2,231 ± 46 | 2,221 ± 36 | 2,205 ± 26 | 2,184 ± 33 | 2,215 ± 29 | 2,128 ± 24 | 2,171 ± 28
Total Labeled Cells | 36 ± 5* | 30 ± 8 | 28 ± 5 | 22 ± 6 | 18 ± 3 | 23 ± 2 | 67 ± 21 | 75 ± 12
Labeling Index (%) | 1.63 ± 0.24* | 1.35 ± 0.35 | 1.25 ± 0.24 | 0.98 ± 0.29 | 0.85 ± 0.14 | 1.05 ± 0.08 | 3.16 ± 1.02 | 3.45 ± 0.52

Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

^a^ Data are presented as mean ± standard error.

^b^ Differences from the vehicle control group are not significant by the Dunn test.

Hepatic acetanilide-4-hydroxylase (A4H) was significantly increased in all dosed groups at week 14 (core study rats) compared to the vehicle control group, with a maximal induction of 3.6-fold at 3 mg/kg/day (Table 6; [underlined: Appendix F]). A4H activity in the 10 and 25 mg/kg/day groups was less than that in the 3 mg/kg/day group. Hepatic pentoxyresorufin-O-deethylase (PROD) activity was significantly increased in all dosed groups at week 14 compared to the vehicle control group, with a maximal induction of 37.5-fold at 3 mg/kg/day (Table 6; Appendix F). In the 10 and 25 mg/kg/day groups, PROD activity decreased in a dose-dependent manner compared to the 3 mg/kg/day group. 7-Ethoxyresorufin-O-deethylase (EROD) activity was higher in all dosed groups compared to the vehicle control group, reaching statistical significance in the ≥0.3 mg/kg/day dosed groups, and continued to increase up to 9.5-fold in the 25 mg/kg/day group (Table 6; [underlined: Appendix F]).

Table 6 Summary of Hepatic Cytochrome P450 Data for Female Rats in the Gavage Studies of Hexachlorobenzene^a,b^

| 0 mg/kg/day | 0.03 mg/kg/day | 0.1 mg/kg/day | 0.3 mg/kg/day | 1 mg/kg/day | 3 mg/kg/day | 10 mg/kg/day | 25 mg/kg/day
n
Week 14 | 10 | 9 | 10 | 10 | 10 | 10 | 10 | 10
Week 21 | 5 | 5 | –^c^ | – | – | – | – | 5
Week 29 | 5 | 5 | – | – | – | – | – | 5
A4H (nmol/minute/mg protein)
Week 14 | 0.465 ± 0.028** | 0.560 ± 0.030* | 0.524 ± 0.020* | 0.626 ± 0.019** | 0.978 ± 0.042** | 1.669 ± 0.090** | 0.965 ± 0.182** | 0.691 ± 0.169**
Week 21 | 0.354 ± 0.018** | 0.286 ± 0.025 | – | – | – | – | – | 0.173 ± 0.018**
Week 29 | 0.285 ± 0.041 | 0.256 ± 0.041 | – | – | – | – | – | 0.313 ± 0.039
EROD (pmol/minute/mg protein)
Week 14 | 35.9 ± 4.1** | 43.0 ± 2.8 | 42.4 ± 1.9 | 48.1 ± 3.8** | 107.7 ± 5.9** | 284.2 ± 23.0** | 314.1 ± 52.3** | 339.7 ± 67.7**
Week 21 | 26.9 ± 1.9 | 20.3 ± 2.0 | – | – | – | – | – | 71.7 ± 11.7
Week 29 | 24.1 ± 3.7** | 27.0 ± 3.0 | – | – | – | – | – | 67.8 ± 7.6**
PROD (pmol/minute/mg protein)^d^
Week 14 | 1.77 ± 0.14** | 2.94 ± 0.11** | 4.39 ± 0.22** | 9.07 ± 0.65** | 21.71 ± 0.98** | 66.30 ± 4.57** | 38.94 ± 5.41** | 28.19 ± 2.63**

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

A4H = acetanilide-4-hydroxylase; EROD = 7-ethoxyresorufin-O-deethylase; PROD = pentoxyresorufin-O-deethylase.

^a^ Data are presented as mean ± standard error. Core study rats were necropsied at 3 months (week 14); elimination study rats were necropsied at week 21 or at week 29.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ Not applicable.

^d^ PROD activity was assayed only at week 14.

Pulmonary EROD activity was significantly increased (7.8-fold from vehicle control animals) only at week 14 in rats administered 25 mg/kg/day HCB (Table 7; [underlined: Appendix F]). Pulmonary PROD and A4H activities were not evaluated.

Table 7 Summary of Pulmonary 7-Ethoxyresorufin-O-deethylase Activity for Female Rats in the Gavage Studies of Hexachlorobenzene^a,b^

| 0 mg/kg/day | 0.03 mg/kg/day | 0.1 mg/kg/day | 0.3 mg/kg/day | 1 mg/kg/day | 3 mg/kg/day | 10 mg/kg/day | 25 mg/kg/day
n
Week 14 | 10 | 9 | 10 | 10 | 10 | 10 | 10 | 10
Week 21 | 5 | 5 | –^c^ | – | – | – | – | 5
Week 29 | 5 | 5 | – | – | – | – | – | 5
EROD (pmol/minute/mg protein)
Week 14 | 0.628 ± 0.110** | 0.958 ± 0.229 | 0.538 ± 0.067 | 0.621 ± 0.082 | 0.885 ± 0.136 | 0.338 ± 0.063 | 0.843 ± 0.100 | 4.872 ± 0.903**
Week 21 | (d) | (d) | – | – | – | – | – | (d)
Week 29 | (d) | (d) | – | – | – | – | – | (d)

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

EROD = 7-ethoxyresorufin-O-deethylase.

^a^ Data are presented as mean ± standard error. Core study rats were necropsied at 3 months (week 14); elimination study rats were necropsied at week 21 or at week 29.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ Not applicable.

^d^ EROD measurements were below the limit of detection.

### Hexachlorobenzene Concentrations in Blood and Tissues

Concentrations of HCB were determined in blood, liver, lung, and adipose tissue after dosing for 3 months (Table 8; Appendix F). The limit of detection of HCB was 2.2 ng/mL, 0.24 ng/g, 0.91 ng/g, and 0.88 ng/g in blood, liver, lung, and adipose tissue, respectively. HCB was detected in all tissues of vehicle control animals but was below the limit of detection in the blood for 6 of 10 samples. Concentrations of HCB in blood and tissues increased generally in proportion to dose. The highest concentrations of HCB were found in the adipose tissue, followed by the liver; concentrations in the lung and blood were similar to each other. Concentrations of HCB in the adipose tissue were 41- to 64-fold higher than concentrations of HCB in the blood. Liver HCB concentrations were 1.8- to 3.1-fold higher than blood HCB concentrations. Lung HCB concentrations were 2.4-fold and 4.3-fold higher than blood concentrations for the 0.03 and 0.1 mg/kg/day groups, respectively; concentrations were approximately equivalent (approximately onefold) for doses ≥0.3 mg/kg/day. The fold difference between HCB concentrations in tissues compared to blood tended to decrease with increasing dose.

Table 8 Summary of Concentrations of Hexachlorobenzene in Blood and Tissues for Core Study Female Rats in the Three-month Gavage Study of Hexachlorobenzene^a,b^

| 0 mg/kg/day | 0.03 mg/kg/day | 0.1 mg/kg/day | 0.3 mg/kg/day | 1 mg/kg/day | 3 mg/kg/day | 10 mg/kg/day | 25 mg/kg/day
n
Blood | 10 | 9 | 10 | 10 | 10 | 10 | 10 | 8^c^
Liver | 9^d^ | 9 | 10 | 10 | 10 | 10 | 10 | 10
Lung | 10 | 9 | 10 | 10 | 10 | 10 | 10 | 10
Adipose | 10 | 9 | 10 | 10 | 10 | 10 | 10 | 10
Tissue Hexachlorobenzene Concentration
Blood (ng/mL) | 1.88 ± 0.362**^e^ | 144 ± 5.11** | 451 ± 18.4** | 1,350 ± 68.2** | 5,050 ± 277** | 15,400 ± 620** | 50,400 ± 1,840** | 152,200 ± 7,070**
Liver (ng/g) | 27.0 ± 1.74** | 422 ± 38.0** | 1,120 ± 75.9** | 4,140 ± 225** | 11,800 ± 486** | 37,700 ± 1,400** | 119,000 ± 5,420** | 270,000 ± 15,700**
Lung (ng/g) | 196 ± 56.5** | 342 ± 53.5 | 1,960 ± 487** | 1,830 ± 166** | 4,640 ± 338** | 22,000 ± 2,510** | 73,200 ± 12,800** | 150,000 ± 15,300**
Adipose (µg/g) | 0.627 ± 0.0761** | 9.24 ± 0.450** | 25.2 ± 1.36** | 65.9 ± 2.93** | 251 ± 8.65** | 766 ± 29.8** | 2,380 ± 98.8** | 6,260 ± 181**

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

^a^ Data shown as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ Sample volume was not sufficient for analysis.

^d^ One value was excluded as an outlier.

^e^ Of 10 samples, 6 were below the limit of detection (LOD) of 2.2 ng/mL. Because 20% of the animals in this group were above the LOD, one-half the LOD value (1.1 ng/mL) was substituted for values that were below the LOD.

### Pathology

This section describes the statistically significant or biologically noteworthy changes in the incidences of nonneoplastic lesions of the liver, lung, spleen, mammary gland, skin, thymus, and teeth. Summaries of the incidences of nonneoplastic lesions and statistical analyses of primary nonneoplastic lesions are presented in [underlined: Appendix F]. Average severity grades of 1 for minimal, 2 for mild, 3 for moderate, and 4 for marked were used in affected animals.

Liver: There was a significant increase in the incidences of hepatocyte hypertrophy in the 10 and 25 mg/kg/day groups compared to the vehicle control group (Table 9). Hepatocyte hypertrophy was diagnosed when hepatocytes (generally centrilobular) were enlarged and had pale eosinophilic cytoplasm. The cytoplasm was increasingly clear with increased enlargement. Hepatocyte nuclei were normal in size, although more bi- and trinucleated hepatocytes were noted in affected livers. Dose-related increases in liver weights were attributed to hepatocellular hypertrophy.

Table 9 Incidences of Select Nonneoplastic Lesions in Core Study Female Rats in the Three-month Gavage Study of Hexachlorobenzene^a^

| 0 mg/kg/day | 0.03 mg/kg/day | 0.1 mg/kg/day | 0.3 mg/kg/day | 1 mg/kg/day | 3 mg/kg/day | 10 mg/kg/day | 25 mg/kg/day
n ^b^ | 10 | 10 | 10 | 10 | 10 | 10 | 10 | 10
Liver
Hepatocyte hypertrophy^c^ | 0** | 0 | 0 | 0 | 0 | 0 | 9** (1.1)^d^ | 10** (1.3)
Lung
Inflammation, chronic | 3** (1.0) | 1 (1.0) | 1 (1.0) | 2 (1.0) | 7 (1.3) | 8* (1.6) | 10** (1.7) | 10** (1.9)
Spleen
Lymphoid hyperplasia | 0** | 0 | 0 | 0 | 0 | 0 | 6** (1.0) | 8** (1.0)
Mammary Gland
Hyperplasia | 2** (1.0) | 2 (2.0) | 1 (1.0) | 0 | 2 (1.0) | 2 (1.0) | 3 (1.3) | 10** (1.2)
Skin
Inflammation, suppurative | 0** | 0 | 0^e^ | 0 | 0 | 0^e^ | 0 | 9** (2.4)
Ulcer | 0** | 0 | 0^e^ | 0 | 0 | 0^e^ | 0 | 7** (1.6)
Thymus
Atrophy | 0** | 1 (4.0)^f^ | 0 | 0 | 0 | 0 | 0 | 3 (1.0)
Teeth
Maxillary incisor, degeneration | 0** | 0 | 0 | 0 | 5* (1.0) | 10** (1.5) | 10** (2.1) | 10** (2.9)

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) or Fisher’s exact (pairwise) test.

^b^ Number of animals examined microscopically.

^c^ Number of animals with lesion.

^d^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^e^ n = 9.

^f^ Animal was euthanized moribund, and a mammary neoplasia was observed upon necropsy.

Lung: There was a significant increase in the incidences of pulmonary chronic inflammation in the 3, 10, and 25 mg/kg/day groups compared to the vehicle control group (Table 9). Chronic inflammation consisted of mixed cellular infiltrates composed of mononuclear cell infiltration characterized by the presence of mononuclear cells (largely lymphocytic), fewer plasma cells within the interstitium, and macrophages within the alveoli. Chronic inflammation might have contributed to the increased lung weights.

Spleen: There was a significant increase in the incidences of splenic lymphoid hyperplasia in the 10 and 25 mg/kg/day dosed groups compared to the vehicle control group (Table 9). Splenic lymphoid hyperplasia was characterized by an increase in thickness of the marginal zone of lymphoid follicles, relative to the follicle center.

Mammary gland: There was a significant increase in the incidences of mammary gland hyperplasia in the 25 mg/kg/day group compared to the vehicle control group (Table 9). Hyperplasia of the alveoli is defined as a relative increase of tubuloalveolar patterns of growth, characterized by alveoli with or without vacuoles within the alveolar epithelium and attached to or close to branched, linear arrays of hypertrophied ducts. The severity was graded as mild if there was evidence of secretion within the hyperplastic glands.

Skin: There was a significant increase in the incidences of skin ulceration and suppurative inflammation in the 25 mg/kg/day group compared to the vehicle control group (Table 9). These lesions correlated with the grossly observed crusts affecting the skin of the face and head.

Thymus: Thymic atrophy was noted in 1 animal in the 0.03 mg/kg/day group and in 3 of 10 animals in the 25 mg/kg/day group (Table 9). Thymic atrophy was characterized by reduced density of lymphocytes in the thymic cortex or when foci were found within the thymus in which the cortex and medulla were reduced, as well as when the epithelial component(s) were more prominent. The animal in the 0.03 mg/kg/day group was euthanized moribund, and the thymic atrophy was determined to be secondary to the stress of the mammary neoplasia observed upon necropsy. There were no significant differences in thymus weight in dosed groups compared to the vehicle control group. The three animals in the 25 mg/kg/day group did not have notably smaller thymuses.

Teeth: There was a significant increase in the incidences of region-specific unilaterally or bilaterally symmetrical (when present) maxillary incisor degeneration in the ≥1 mg/kg groups compared to the vehicle control group (Table 9). The molars were unaffected by exposure.^130^ The number of animals affected and the severity of the maxillary incisor degeneration increased in a dose-dependent manner.

The grading scheme used for maxillary incisor degeneration was as follows. Incisor degeneration was graded on a scale of 0–4, with 0 representing no lesion, 1 representing minimal degeneration, 2 representing mild degeneration, 3 representing moderate degeneration, and 4 representing severe degeneration.

- Grade 0 (no lesion) normal incisor was characterized by having no significant microscopic lesions.
- Grade 1 (minimal) incisor degeneration was characterized by focal pulp alteration.
- Grade 2 (mild) incisor degeneration was characterized by focal or multifocal pulp alteration with focal odontoblast degeneration.
- Grade 3 (moderate) incisor degeneration was characterized by multifocal pulp alteration and multifocal odontoblast degeneration.
- Grade 4 (severe) incisor degeneration was characterized by multifocal pulp alteration, multifocal odontoblast degeneration, and complete discontinuities in the dentin surrounding the pulp chamber.

Administration of 1 mg/kg/day HCB resulted in focal mesenchymal cell vacuolation and focal osteodentin formation within the pulp (Figure 3). Lesions were restricted to a short linear region subjacent to the odontoblast layer along the lateral aspect of the incisor at the level of the dentin-enamel interface. When observed in both incisors, lesions were bilaterally symmetrical. Administration of 3 mg/kg/day resulted in lateral and medial pulp lesions and focal odontoblast degeneration with dentin niche formation along the lateral incisor margin in some animals. Administration of 10 mg/kg/day resulted in a higher incidence of lateral dentin niches and a lower incidence of medial dentin niches (Figure 4). In animals administered 25 mg/kg/day HCB, a high incidence of bilaterally symmetrical, lateral and medial, dentin niches was observed (Figure 5). (Compare Figure 4 and Figure 5 with normal aspect in the vehicle control animal in Figure 6.) There was no evidence of hemorrhage, thrombosis, or vasculitis.

Figure 3

Level II Section of a Maxillary Incisor Tooth from a Female Rat Administered 1 mg/kg/day Hexachlorobenzene Showing Minimal Incisor Degeneration

Note vacuolation of pulp mesenchymal cells (arrows) and osteodentin formation (arrow heads). Odontoblasts (O) are unaffected.

Figure 4

Level II Section of a Maxillary Incisor Tooth from a Female Rat Administered 10 mg/kg/day Hexachlorobenzene

Note mild degeneration in the maxillary incisor, characterized by focal pulp and odontoblast degeneration and formation of a dentin niche (arrow) along the lateral aspect of the maxillary incisor.

Figure 5

Level II Section of a Maxillary Incisor Tooth from a Female Rat Administered 25 mg/kg/day Hexachlorobenzene

Note lateral (large) and medial (small) dentin niche defects (arrows) in maxillary incisor.

Figure 6

Level II Section of a Maxillary Incisor Tooth from a Vehicle Control Female Rat

Note pulp (P), odontoblasts (O), dentin (D), enamel (E), and ameloblasts (arrows).

## Determination of Relative Potency Factors

To generate relative potency factors (RPFs) for the determination of a toxic equivalency factor (TEF), data obtained from this study were compared with data from the 3-month time point of the 2-year bioassay on 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD), which was conducted as part of the TEF studies at NTP.^108^ RPFs of TCDD congeners are typically estimated by comparing the median effective dose (ED_50_), no-observed-effect level (NOEL), or lowest-observed-effect level (LOEL) for a response. Use of ED_50_ is preferred, as it reduces uncertainty related to the NOEL or LOEL.^112^ Ideally, determination of the ED_50_ requires that the maximal response be similar for both TCDD and the congener, which should also have parallel dose-response curves.^112^ If the maximal response data are not available, alternative methods can be used to determine if dose-response curves are parallel.^131^ Endpoints selected for RPF determination were thyroid hormone levels, hepatic cell proliferation, and hepatic and pulmonary CYP enzyme activity. These endpoints were selected because they are well-characterized, aryl hydrocarbon (Ah) receptor-mediated effects seen with TCDD exposure and because these endpoints were also assessed at the 3-month interim time point in the 2-year TCDD bioassay. Dose-response curves for HCB and TCDD for select endpoints are shown in Figure 7 and Figure 8; parameters describing model goodness of fit for both data sets are shown in Table 10.

Figure 7

Dose-response Curves for Plasma Free and Total Thyroxine, Triiodothyronine, and Thyroid Stimulating Hormone Levels in Female Rats Administered Hexachlorobenzene or 2,3,7,8Tetrachlorodibenzo-p-dioxin by Gavage for Three Months

T_3_ = triiodothyronine; T_4_ = thyroxine; TSH = thyroid stimulating hormone; HCB = hexachlorobenzene; TCDD = 2,3,7,8-tetrachlorodibenzo-p-dioxin.

Figure 8

Dose-response Curves for Cytochrome P450 Enzyme Activity in the Liver (A–C) and Lung (D) of Female Rats Administered Hexachlorobenzene or 2,3,7,8-Tetrachlorodibenzo-p-dioxin by Gavage for Three Months

A-4-H = acetanilide-4-hydroxylase; EROD = 7-ethoxyresorufin-O-deethylase; PROD = pentoxyresorufin-O-deethylase;

HCB = hexachlorobenzene; TCDD = 2,3,7,8-tetrachlorodibenzo-p-dioxin.

Table 10 Nonlinear Curve Goodness-of-Fit Values of Select Endpoints Evaluated in Female Rats Administered Hexachlorobenzene or 2,3,7,8-Tetrachlorodibenzo-p-dioxin by Gavage for Three Months

Endpoint | Model | R^2^ for HCB Data | R^2^ for TCDD Data
Free Thyroxine | One-phase association | 0.68 | 0.18
Total Thyroxine | One-phase association | 0.79 | 0.35
Total Triiodothyronine | One-phase association | 0.21^a^ | 0.94
Thyroid Stimulating Hormone | One-phase association | 0.007 | 0.86
Hepatic Proliferation | One-phase association | 0.27 | 0.08
Hepatic A4H | One-phase association | 0.32 | 0.90
Hepatic EROD | Specific binding with Hill slope | 0.61 | 0.86
Hepatic PROD | One-phase association | 0.64 | 0.93
Pulmonary EROD | Exponential growth equation | 0.63 | 0.47

HCB = hexachlorobenzene; TCDD = 2,3,7,8-tetrachlorodibenzo-p-dioxin; A4H = acetanilide-4-hydroxylase; EROD = 7-ethoxyresorufin-O-deethylase; PROD = pentoxyresorufin-O-deethylase.

^a^ Model not converged.

At 3 months, free and total T_4_ were significantly decreased, and T_3_ and TSH were significantly increased in the two highest TCDD doses compared to vehicle control animals in the TCDD study (Figure 7A–D).^108^ For all thyroid hormones measured, determining an HCB RPF was not possible for a variety of reasons. For free and total T_4_, HCB induced more than a 90% decrease in the hormones, whereas TCDD appeared to produce a maximal 40% decrease. Higher doses of TCDD may produce further decreases in T_4_. Because the maximum decreases for HCB and TCDD were not similar for these hormones given the available data, deriving an RPF at this point is not appropriate (Figure 7A, B). For total T_3_, the dose-response curve diverged at the highest doses of HCB and TCDD (Figure 7C). In other words, at the highest dose of HCB, T_3_ was decreasing, whereas at the highest doses of TCDD, an increasing trend was observed. There was no effect on TSH in animals administered HCB with this dose range (Figure 7D). Thus, these data indicate that HCB alters thyroid hormones likely through a different mechanism than TCDD. Because the dose-response curves differ, deriving an RPF for changes in thyroid hormones is inappropriate.

Minimal changes in hepatic cell proliferation occurred after TCDD administration at 3 months at the doses tested.^108^ Due to the minimal response in proliferation, modeling for both TCDD and HCB was poor and inhibited the determination of an RPF.

In the 2-year TCDD bioassay, all doses increased hepatic A4H, EROD, and PROD and pulmonary EROD activity at 3 months.^108^ Modeling of HCB and TCDD enzyme activity data from both hepatic and pulmonary preparations showed stark differences in the maximum plateau levels (Figure 8). TCDD had higher plateaus in enzyme activity than did HCB with the exception of hepatic PROD activity. Comparing ED_50_ for these dose-response curves with different maximal responses is not applicable for RPF determination.

## Genetic Toxicology

HCB (100 to 10,000 μg/plate) was not mutagenic in Salmonella typhimurium strains TA98, TA100, TA1535, or TA1537, with or without rat or hamster liver S9 activation enzymes (Appendix E).^93^

## Elimination Study

After dosing for 13 weeks (day 90), animals in the elimination study were held without dosing until necropsy at 21 (day 146) or 29 (day 201) weeks. At week 21, animals administered HCB had slightly higher body weights compared to vehicle control animals (9% and 12% higher in the 0.03 and 25 mg/kg/day groups, respectively), although not statistically significant (Table 11; [underlined: Appendix F]). Mean body weights were similar across all dosed groups at week 29 (Table 11; [underlined: Appendix F]). Absolute and relative liver weights were significantly increased in the high-dose (25 mg/kg/day) group at both 21 and 29 weeks (Table 11; [underlined: Appendix F]). No significant differences in absolute or relative weights of the lung, thymus, and thyroid gland were observed. Rats in the 25 mg/kg/day group had significantly decreased hepatic A4H activity at week 21 and significantly increased hepatic EROD activity at week 29 (Table 6; [underlined: Appendix F]) compared to vehicle control animals. Hepatic PROD was not evaluated in elimination study samples, and pulmonary EROD activities are not discussed due to values being below the limit of detection (Table 7; [underlined: Appendix F]).

Table 11 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Elimination Study Female Rats in the Three-month Gavage Study of Hexachlorobenzene^a,b^

| 0 mg/kg/day | 0.03 mg/kg/day | 25 mg/kg/day
n | 5 | 5 | 5
Day 146
Necropsy Body Wt. (g) | 267.5 ± 10.2 | 292.9 ± 14.2 | 301.5 ± 10.7
Liver
Absolute (g) | 7.78 ± 0.24** | 9.16 ± 0.83 | 10.87 ± 0.63**
Relative (mg/g) | 29.19 ± 1.09** | 31.10 ± 1.37 | 35.98 ± 0.98**
Day 201
Necropsy Body Wt. (g) | 300.5 ± 7.2 | 289.5 ± 10.8 | 305.0 ± 12.2
Liver
Absolute (g) | 8.72 ± 0.44 | 8.91 ± 0.19 | 10.34 ± 0.55*
Relative (mg/g) | 29.05 ± 1.42* | 30.95 ± 1.34 | 33.86 ± 0.77*

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

Concentrations of HCB were determined in blood every 2 weeks for 16 weeks after cessation of exposure (Table 12; [underlined: Appendix F]). The half-life of HCB in blood was calculated using a first-decay elimination model and was estimated to be 53 (0.03 mg/kg/day) and 48 (25 mg/kg/day) days. Tissue concentrations were evaluated at weeks 21 and 29 (Table 13; [underlined: Appendix F]). Concentrations in the liver and lung were about equivalent (generally less than twofold difference) to that in blood at both time points. At week 29, however, concentrations of HCB in the adipose tissue were 37- to 58-fold higher than blood HCB concentrations, demonstrating retention of HCB in this tissue. As in the core study, the difference between tissue and blood HCB concentrations was smaller in the 25 mg/kg/day dosed group compared to the 0.03 mg/kg/day dosed group at both time points. The concentration of HCB in tissues decreased over 8 weeks (comparing concentrations at weeks 21 and 29) by 35%, 58%, and 9% in the adipose tissue, liver, and lung, respectively, in animals from the 0.03 mg/kg/day group (Table 13; [underlined: Appendix F]). In the 25 mg/kg/day group, tissue concentrations decreased by 44%, 44%, and 13% in the adipose tissue, liver, and lung, respectively (Table 13; [underlined: Appendix F]).

Table 12 Summary of Concentrations of Hexachlorobenzene in Blood for Elimination Study Female Rats in the Three-month Gavage Study of Hexachlorobenzene^a,b^

Day | Blood (ng/mL)
Day | 0 mg/kg/day | 0.03 mg/kg/day | 25 mg/kg/day
n ^c^ | 10 | 10 | 10
90 | 63.6 ± 5.87**^d^ | 187 ± 9.66**^d^ | 131,000 ± 4,650**^d^
n | 5 | 5 | 5
104 | 49.5 ± 1.39** | 176 ± 3.93** | 126,000 ± 3,990**
118 | 64.7 ± 4.17** | 140 ± 6.76** | 94,800 ± 1,310**
132 | 50.2 ± 3.47** | 110 ± 2.71** | 78,200 ± 3,850**
146 | 43.9 ± 2.53** | 87.2 ± 6.09** | 62,400 ± 2,180**
160 | 54.0 ± 1.32** | 85.7 ± 3.96** | 53,700 ± 2,310**
174 | 41.5 ± 0.893** | 76.6 ± 3.08** | 50,900 ± 1,350**
201 | 33.4 ± 3.25** | 59.8 ± 1.87** | 45,700 ± 778**

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ Number of samples per group. Blood was obtained from 10 animals per group on day 90. Five animals per group were sampled on days 104, 132, and 146; the other five animals per group were sampled on days 118, 160, 174, and 201 via the retroorbital plexus.

^d^ Average of values from both cohorts.

Table 13 Summary of Concentrations of Hexachlorobenzene in Tissues for Elimination Study Female Rats in the Three-month Gavage Study of Hexachlorobenzene^a,b^

Day | Liver (ng/g) | | | Lung (ng/g) | | | Adipose (µg/g)
Day | 0 mg/kg/day | 0.03 mg/kg/day | 25 mg/kg/day | 0 mg/kg/day | 0.03 mg/kg/day | 25 mg/kg/day | 0 mg/kg/day | 0.03 mg/kg/day | 25 mg/kg/day
n | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5
146 | 118 ± 4.11** | 193 ± 17.0** | 109,000 ± 8,450** | 63.9 ± 9.91** | 90.0 ± 8.71 | 37,500 ± 4,630** | 2.72 ± 0.277** | 5.27 ± 0.126** | 3,040 ± 91.1**
201 | 55.7 ± 1.62** | 81.0 ± 4.89** | 60,900 ± 3,170** | 50.6 ± 5.58** | 82.3 ± 13.0* | 32,700 ± 2,730** | 1.82 ± 0.103** | 3.45 ± 0.295** | 1,690 ± 66.7**

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.