# Materials and Methods

## Procurement and Characterization

### Hexachlorobenzene

Hexachlorobenzene (HCB) was obtained from Aldrich Chemical Company (Milwaukee, WI) in one lot (03915CU) that was used in the 3-month study. Identity and purity analyses were conducted by the analytical chemistry laboratory at Midwest Research Institute (MRIGlobal, Kansas City, MO); additional identity analyses were conducted by the study laboratory at Battelle (Columbus, OH) (Appendix A). One additional lot (08526EF) was procured from Aldrich Chemical Company by the analytical chemistry laboratory solely for dose formulation stability studies. Reports on analyses performed in support of the HCB study are on file at the National Institute of Environmental Health Sciences (NIEHS).

The chemical, a white powder, was identified as HCB by the analytical chemistry laboratory using infrared (IR) spectroscopy and gas chromatography (GC) coupled with mass spectrometry. The study laboratory confirmed the identity of the test article by IR spectroscopy.

The purity of lot 03915CU was determined by GC with flame ionization detection (GC/FID). The purity assay indicated one major peak and one impurity with a peak area equal to 0.05% of the total peak area. The overall purity of lot 03915CU was determined to be >99%.

After the scheduled termination of the animals, bulk chemical reanalysis was performed by the study laboratory using GC/FID, and no degradation of the bulk chemical was detected. To ensure stability, the bulk chemical was stored at room temperature in an amber glass bottle.

### Formulation Materials

United States Pharmacopeia (USP)-grade corn oil was obtained from Spectrum Quality Products (Gardena, CA) in two lots and was used with one lot of USP-grade acetone (Spectrum Quality Products) as the vehicle in the 3-month gavage study. The identity of the acetone was confirmed by the study laboratory using IR spectroscopy prior to its use. Purity of the acetone was determined to be ≥99.9% by the study laboratory using GC/FID. The corn oil was analyzed twice by the study laboratory for peroxide levels by potentiometric titration; both measured values were below the rejection criterion of 3 mEq/kg.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared by mixing stock solutions of HCB with the vehicle (corn oil:acetone [99:1]) to achieve the required concentrations (Table A-2). The dose formulations were stored in amber glass bottles sealed with Teflon^®^-lined lids at room temperature for up to 34 days.

The study laboratory determined that a 10 mg/mL dose formulation was gavagable using a 20-gauge needle.

Homogeneity studies of the 0.012 and 10.0 mg/mL dose formulations in corn oil:acetone (99:1) were performed by the study laboratory using GC with electron capture detection (ECD). Stability studies of a 1 μg/mL dose formulation made with lot 08526EF dissolved in 100% corn oil were performed by the analytical chemistry laboratory using GC/ECD. Homogeneity was confirmed, and stability for at least 35 days was confirmed for dose formulations stored in sealed containers in the dark at 5°C and 25°C and for at least 3 hours under simulated animal room conditions.

Periodic analyses of the dose formulations of HCB were conducted by the study laboratory using GC/ECD. During the 3-month study, the dose formulations were analyzed at the beginning, midpoint, and termination; all 21 dose formulations were within 10% of the target concentrations (Table A-3). Animal room samples of these dose formulations were also analyzed; 20 of 21 animal room samples were within 10% of the target concentrations.

## Animal Source

Female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were obtained from Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN).

## Animal Welfare

Animal care and use were in accordance with Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the Battelle (Columbus, OH) Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health and National Toxicology Program (NTP) animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Core Study

Rats were approximately 6 weeks old upon receipt, were quarantined for 13 days, and were 8 weeks old when placed on study. Before the study began, 10 female rats were randomly selected for parasite evaluation and gross observation for evidence of disease. Blood samples were collected from 10 sentinel female rats at 4 weeks and from 9 sentinel female rats at study termination. The sera were analyzed for antibody titers to rodent viruses.^109-111^ Additionally, the health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Groups of 10 female rats were administered doses of 0.03, 0.1, 0.3, 1, 3, 10, or 25 mg HCB/kg body weight/day (mg/kg/day) in corn oil:acetone (99:1) by gavage 5 days per week for 13 weeks (3 months). Ten vehicle control female rats were administered the corn oil:acetone vehicle only. The dosing volume was 2.5 mL/kg body weight. Dose selection for this study was informed by the NTP 2-year study of 3,3’,4,4’,5-pentachlorobiphenyl (PCB 126)^106^ and used relative potency values of 0.1 for PCB 126 and 0.0001 for HCB.^112^ Accordingly, HCB concentrations needed to be 1,000 times greater than those used in the PCB 126 study (10–1,000 ng/kg/day). Additionally, previous chronic exposure studies of HCB in Sprague Dawley rats suggested that the range 0.3–25 mg/kg sufficiently covered the no-observed-effect level and lowest-observed-effect level for pertinent endpoints.^72,113,114^

Feed and water were available ad libitum; information on feed composition and contaminants is provided in Appendix B. Rats were housed five per cage. Clinical findings were recorded at the study start, weekly thereafter, and at necropsy. Rats were weighed at study start, weekly for 13 weeks, and at necropsy.

At study termination (1 day after the last dose), blood was collected by cardiac puncture and processed into serum for thyroid hormone analyses. Radioimmunoassays were performed for thyroid stimulating hormone (TSH), total triiodothyronine (T_3_), and free thyroxine (T_4_) using a Packard Cobra II gamma counter (Packard Instrument Company, Meriden, CT). The assay for total T_4_ was performed on a Hitachi 911^®^ chemistry analyzer (Boehringer Mannheim, Indianapolis, IN) using a Boehringer Mannheim^®^ enzyme immunoassay test system. Thyroid hormone data were summarized using the XYBION system (XYBION Medical Systems Corporation, Cedar Knolls, NJ).

For cell proliferation analyses, all core study rats received drinking water containing 40 mg bromodeoxyuridine (BrdU)/100 mL Milli-Q water for 5 days before necropsy. BrdU solutions were administered in amber glass water bottles (Allentown Caging Equipment Company, Inc., Allentown, NJ) equipped with Teflon-lined lids and stainless-steel sipper tubes. Water consumption was measured daily for 5 days. The cell turnover rate in the liver of dosed rats was compared with the turnover rate in the vehicle control rats by determining the incorporation of BrdU into hepatocytes. A sample of duodenum (positive control) and liver was fixed in 10% neutral buffered formalin for 18 to 24 hours and then transferred to 70% ethanol. Representative sections of the duodenum and liver were trimmed and embedded, and two sections were cut. One section was stained with hematoxylin and eosin (H&E) and the other with anti-BrdU antibody complexed with avidin and biotin. Potential interlobular variation was determined in the vehicle control and 25 mg/kg/day groups by counting stained cells in the left lobe and right median lobe. Interlobular variation >25% was considered significant. For the remaining core study rats, stained cells only in the left lobe were counted. At least 2,000 labeled or unlabeled hepatocyte nuclei were counted using a 20× objective and an ocular grid. The labeling index is expressed as the percentage of total nuclei labeled with BrdU.

For determination of cytochrome P450 (CYP) activities, liver and lung tissue samples were collected at necropsy and stored frozen at −70°C. Microsomal suspensions were prepared using the Pearce Method.^115^ The concentration of each protein in each suspension was determined using the microtiter plate method of the Coumassie^®^ Plus Protein Assay (Pierce Chemical Co., Rockford, IL) with bovine serum albumin as the standard. CYP1A1-associated 7-ethoxyresorufin-O-deethylase (EROD), CYP1A2-associated acetanilide-4-hydroxylase (A4H), and CYP2B-associated pentoxyresorufin-O-deethylase (PROD) activities were determined in microsomal proteins isolated from frozen liver tissue according to established procedures. Only EROD activity was evaluated in microsomal proteins isolated from frozen lung tissue. Data are shown as pmol/minute/mg (EROD and PROD) or nmol/minute/mg (A4H) microsomal protein.

For analyses of HCB tissue concentrations, adipose, liver, and lung samples were taken from all animals at necropsy. Blood was collected via cardiac puncture from 10 core study rats per group at necropsy, mixed with heparin, and refrigerated at 5°C.

Necropsies were performed on all rats. At necropsy, the liver, right kidney, lung, left ovary, spleen, thymus, and thyroid gland were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin, processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 μm, and stained with H&E. Complete histopathological examinations were performed on vehicle control and 25 mg/kg/day groups. Table 1 lists the tissues and organs examined.

Table 1 Experimental Design and Materials and Methods in the Three-month Gavage Study of Hexachlorobenzene

Three-month Study
Study Laboratory
Battelle (Columbus, OH)
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats
Animal Source
Envigo (formerly Harlan Laboratories, Inc.; Indianapolis, IN)
Time Held Before Study
Core study: 13 days
Elimination study: 14 days
Average Age When Study Began
8 weeks
Date of First Dose
Core study: January 10, 2001
Elimination study: January 11, 2001
Duration of Dosing
13 weeks (3 months)
Date of Last Dose
Core study: April 11, 2001
Elimination study: April 10, 2001
Necropsy Dates
Core study: April 12, 2001
Elimination study: June 5, 2001 or July 30, 2001
Average Age at Necropsy
Core study: 21 weeks
Elimination study: 29 or 36 weeks
Size of Study Groups
10 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights.
Animals per Cage
5
Method of Animal Identification
Tail tattoo
Diet
NTP-2000 irradiated pellet diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed weekly
Water
Tap water (Columbus municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI), except via amber glass bottles during BrdU administration, available ad libitum
Cages
Solid-bottom polycarbonate (Lab Products, Inc., Seaford, DE); changed twice a week
Bedding
Irradiated, heat-treated hardwood chips (P.J. Murphy Forest Products Corp., Montville, NJ); changed twice a week
Cage Filters
DuPont 2024 spun-bonded polyester (Snow Filtration Co., Cincinnati, OH); changed every 2 weeks
Racks
Stainless steel (Lab Products, Inc., Seaford, DE); changed and rotated every 2 weeks
Animal Room Environment
Temperature: 72°F ± 3°F
Relative humidity: 50% ± 15%
Room fluorescent light: 12 hours/day
Room air changes: at least 10/hour
Doses
0, 0.03, 0.1, 0.3, 1, 3, 10, or 25 mg/kg/day (core study) or 0, 0.03, or 25 mg/kg/day (elimination study) in corn oil:acetone (99:1) by gavage (dosing volume 2.5 mL/kg)
Type and Frequency of Observation
Observed twice daily; rats were weighed at study start, weekly for 13 weeks, and at study termination; clinical findings were recorded for core study rats at study start, weekly thereafter, and at study termination.
Method of Euthanasia
100% carbon dioxide
Necropsy
Necropsies were performed on all animals. Organs weighed for core study rats were liver, right kidney, lung, left ovary, spleen, thymus, and thyroid gland. Organs weighed for elimination study rats were liver, lung, thymus, and thyroid gland.
Thyroid Hormone Analysis
At study termination, blood was collected from core study rats by cardiac puncture for thyroid stimulating hormone, total triiodothyronine, and total and free thyroxine determinations.
Cell Proliferation
For 5 days before study termination at 3 months, core study rats received BrdU in drinking water. Samples of liver and duodenum were measured for BrdU labeling.
Cytochrome P450 Activities
At study termination (core study) and at week 21 or 29 (elimination study), tissue samples were taken for 7-ethoxyresorufin-O-deethylase (liver and lung), 7-pentoxyresorufin-O-deethylase (liver, core study only), and acetanilide-4-hydroxylase (liver) activities.
Blood and Tissue Concentration Analyses
At study termination (core study rats) and day 146 and 201 (elimination study rats), adipose, liver, and lung tissue samples were collected. Blood was collected at study termination on day 93 (core study rats); on day 90 (10 elimination study rats); on days 104, 132, and 146 (5 elimination study rats); or on days 118, 160, 174, and 201 (5 elimination study rats). Tissue and blood samples were analyzed for hexachlorobenzene concentrations.
Histopathology
Histopathology was performed on all core study rats in the vehicle control and 25 mg/kg/day groups. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, small intestine (duodenum), kidney, liver, lung, mammary gland, nose, ovary, pancreas, pituitary gland, skin, spleen, stomach (forestomach), teeth, thymus, thyroid gland, tongue, uterus, and vagina. The liver, lung, mammary gland, skin, spleen, teeth, and thymus were examined to a no-effect level in the remaining core study groups. Histopathological evaluation was not done for tissues collected from rats in the elimination study.

After a review of the laboratory reports and selected histopathology slides by a quality assessment pathologist, the findings and reviewed slides were submitted to an NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the laboratory and quality assessment pathologists were resolved by the NTP pathology peer-review process. Final diagnoses for reviewed lesions represent a consensus among the laboratory pathologist, NTP pathologist, reviewing pathologist(s), if any, and the PWG coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^116^ and Boorman et al.^117^

## Elimination Study

A set of animals was allocated to evaluate the clearance of HCB after repeated exposures. Rats were approximately 6 weeks old upon receipt, were quarantined for 14 days, and were 8 weeks old when placed on study. Before the study began, 10 female rats were randomly selected for parasite evaluation and gross observation for evidence of disease. Blood samples were collected from 10 sentinel female rats at 4 weeks and from 9 sentinel female rats at study termination. The sera were analyzed for antibody titers to rodent viruses.^109-111^ Additionally, the health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Groups of 10 female rats were administered 0.03 or 25 mg/kg/day HCB in corn oil:acetone (99:1) by gavage 5 days per week for 13 weeks (3 months) and then held without dosing until necropsy 8 weeks after the last dose (week 21, n = 5) or 16 weeks after the last dose (week 29, n = 5). Ten vehicle control female rats were administered the corn oil:acetone vehicle only. The dosing volume was 2.5 mL/kg body weight. Feed and water were available ad libitum. Rats were housed five per cage. Rats were weighed at study start, weekly for 13 weeks, and at necropsy.

For determination of CYP activities, liver and lung tissue samples were collected at week 21 or 29 and stored frozen at −70°C. Microsomal suspensions were prepared using the Pearce Method.^115^ The concentration of each protein in each suspension was determined using the microtiter plate method of the Coomassie Plus Protein Assay (Pierce Chemical Co., Rockford, IL) with bovine serum albumin as the standard. CYP1A1-associated EROD and CYP1A2-associated A4H activities were determined in microsomal proteins isolated from frozen liver tissue according to established procedures. Only EROD activity was assayed in microsomal proteins isolated from frozen lung tissues. Data are shown as pmol/minute/mg (EROD) or nmol/minute/mg (A4H) microsomal protein.

For analyses of HCB tissue concentrations, adipose, liver, and lung samples were taken from five rats per group at weeks 21 and 29. Blood was collected via retroorbital sinus puncture from elimination study animals. Blood was collected from all 10 rats per group on day 90. On days 104, 132, and 146, blood was collected from five rats per group; blood was collected from the remaining five rats in each group on days 118, 160, 174, and 201. Blood was mixed with heparin and refrigerated at −5°C.

Necropsies were performed on all rats. At necropsy, the liver, lung, thymus, and thyroid gland of all animals were weighed. No microscopic examinations were conducted.

## Analysis of Hexachlorobenzene in Blood and Tissue Samples

Blood and tissue samples were analyzed for HCB concentrations using a validated analytical method (Appendix D). Briefly, 100 μL of blood was added to 100 μL of acetonitrile and extracted with hexane. Tissue samples (0.1–0.3 g) were prepared similarly to blood samples except tissues were homogenized prior to acetonitrile precipitation and hexane extraction. All samples, standards, and blanks were analyzed using GC/ECD.

## Modeling

Elimination study: Concentrations of HCB in blood after cessation of exposure were modeled in GraphPad Prism (La Jolla, CA) using a one-phase decay model to determine the half-life of HCB.

Determination of RPF: Thyroid hormones, hepatic and pulmonary P450 enzyme activities, and hepatocyte proliferation data were modeled in GraphPad Prism (La Jolla, CA). Data for 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD) exposure at these endpoints were taken from NTP Technical Report 521.^108^ Data from HCB and TCDD were fit with various models (one-phase association, specific binding with Hill slope, exponential growth).

## Statistical Methods

### Calculation and Analysis of Nonneoplastic Lesion Incidences

The incidences of nonneoplastic lesions are presented as the numbers of animals bearing such lesions at a specific anatomic site and as the numbers of animals with that site examined microscopically. Fisher’s exact test,^118^ a procedure that uses the overall proportion of affected animals, was used to determine significance between exposed and vehicle control animals, and the Cochran-Armitage trend test was used to test for significant trends.^119^

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and vehicle control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^120^ and Williams.^121,122^ Thyroid hormone, cell proliferation, and cytochrome P450 data, which typically have skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^123^ (as modified by Williams^124^) and Dunn.^125^ The Jonckheere test^126^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (the Williams or Shirley test) was more appropriate for pairwise comparisons than would be a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Before statistical analysis, extreme values identified by the outlier test of Dixon and Massey^127^ were examined by NTP personnel, and implausible values were eliminated from the analysis.

## Quality Assurance Methods

The 3-month studies were conducted in compliance with U.S. Food and Drug Administration Good Laboratory Practice Regulations.^128^ In addition, the 3-month study reports were audited retrospectively by an independent quality assurance contractor against study records submitted to the NTP Archives. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Toxicity Study Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Toxicity Report.

## Genetic Toxicology

The genetic toxicity of HCB was assessed by testing the ability of the chemical to induce mutations in various strains of Salmonella typhimurium. The protocol for these studies and the results are given in Appendix E.

Testing was performed as reported by Haworth et al.^93^ HCB was sent to the laboratory as a coded aliquot from Radian Corporation (Austin, TX). It was incubated with the Salmonella typhimurium tester strains TA98, TA100, TA1535, and TA1537 either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague Dawley rat or Syrian hamster liver) for 20 minutes at 37°C. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted after 2 days of incubation at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and of five doses of HCB. In the absence of toxicity, the high dose was limited by experimental design to 10,000 μg/plate. All trials were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose-related, reproducible, or of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. No minimum percentage or fold-increase is required for a chemical to be judged positive or weakly positive.