# Introduction

Figure 1

Hexachlorobenzene (CASRN 118-74-1; Chemical Formula: C_6_Cl_6_; Molecular Weight: 284.78 g)

Synonyms: benzene hexachloro-; HCB; Hexa CB; pentachlorophenyl chloride; perchlorobenzene.

Trade names: Amatin, Anticarie, Bunt-Cure, Bunt-No-More, Ceku; Co-op Hexa, Granox NM, Julian’s Carbon Chloride, No Bunt, No Bunt 40, No Bunt 80, Sanocide, Smut-Go, Snieciotox.

## Chemical and Physical Properties

Hexachlorobenzene (HCB) is an organohalogen compound with a molecular formula of C_6_Cl_6_.^1^ At room temperature, HCB appears as white needles or prisms. Its water solubility is 0.005 mg/L at 25°C, and it is readily soluble in organic solvents such as benzene, chloroform, and ether.^2^ The estimated log octanol:water partition coefficient of HCB is 5.5.^1^ HCB is a stable, nonreactive compound, which slowly degrades in the environment with an estimated soil half-life between 3 and 6 years.^3^

## Production, Use, and Human Exposure

HCB was used as a fungicide in seed treatment, particularly to control bunt, a fungal disease that affects wheat.^1^ It also was used in the manufacture of pyrotechnics and tracer bullets, as a fluxing agent in the manufacture of aluminum, as a wood preserving agent, as a porosity control agent in the manufacture of graphite anodes, and as a peptizing agent in the production of nitroso and styrene rubber for tires. The use and production of HCB is banned globally under the Stockholm Convention on Persistent Organic Pollutants. In the United States, all registered pesticide uses of HCB were voluntarily canceled in 1984, and it has no current uses as an end product in the United States. HCB remains an industrial by-product in the manufacture of tetrachloroethylene, perchloroethylene, and pentachlorobenzene. It is also a by-product found in several pesticides, such as pentachloronitrobenzene, chlorothalonil, Dacthal^®^, pentachlorophenol, atrazine, simazine, propazine, and maleic hydrazide.^1^ Incineration of municipal waste could be another significant contributor to levels of HCB in the environment.^4,5^

Global production of HCB between 1978 and 1981 was estimated to be 10,000 tons/year.^6^ United States production of HCB in 1973 was estimated at 300 tons (from three producers).^7^ Although no evidence of commercial production was found in the United States in 1982, HCB production as a by-product was estimated at 4,130 tons.^8^ Nearly 77% of this by-product was produced during the manufacture of carbon tetrachloride, trichloroethylene, and tetrachloroethylene.^9^ The U.S. Environmental Protection Agency (EPA) Toxic Release Inventory reports approximately 33,617 pounds of HCB were released in 2010.^10^ Of the 1,613 hazardous waste sites proposed for inclusion on the EPA National Priorities List, HCB has been identified in at least 107.^3^

Because HCB is a persistent bioaccumulative toxicant, consumption of low levels in food is likely a major route of exposure. HCB was detected in multiple food items including meats, dairy products, wheat products, and vegetables collected between 1991 and 2003 for the U.S. Food and Drug Administration’s (FDA’s) Total Diet Study. Average concentrations of HCB in these foods ranged from 0.01 to 0.98 ppb.^11^ Estimates of daily dietary intake in the United States from 1982 through 1984 from the FDA’s Total Diet Study was 1 to 2 ng/kg/day.^12^ Accurate dietary intake estimations are limited by the infrequent (<2%) detection of HCB in particular food items. For example, the Pesticide Data Program (PDP) of the U.S. Department of Agriculture (USDA) found that HCB was below the detection limit of 1 ppb in more than 5,200 samples of fruit, vegetables, and honey.^13^ In contrast, approximately 42% of the heavy cream samples analyzed as part of the USDA PDP had detectable concentrations of HCB ranging from 0.2 to 0.5 ppb.

In the 2003–2004 U.S. National Health and Nutrition Examination Survey (NHANES), 99.9% of the surveyed population had detectable serum HCB concentrations; the geometric mean was 15.9 ng/g lipid in the serum.^14^ In the 2013–2014 NHANES survey, the average concentration of serum HCB for samples pooled by ethnic group and age ranged from 6.18 to 21.6 ng/g lipid.^15^ In 2010, a study found that concentrations of HCB in Mexican-American women of reproductive age born in Salinas, California, ranged from 7.5 to 701 ng/g lipid in serum.^16^ Due to restrictions on use and production, human tissue concentrations of HCB appear to be decreasing globally.^17-19^ For example, in Sweden, tissue concentrations of HCB dropped approximately 8% per year from 1993 through 2007.^19^

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

Numerous absorption, distribution, metabolism, and excretion studies of HCB have been conducted in experimental animals. These studies indicate HCB is readily absorbed orally (~80%) when administered in an oil vehicle.^1,20^ HCB accumulates in tissues with high lipid content such as adipose, adrenal cortex, bone marrow, skin, thyroid gland, adrenal gland, and ovary.^1,21^ HCB has been shown to readily transfer to the fetus, concentrate in milk, and transfer to neonates in rhesus monkeys and Sprague Dawley rats.^22-26^

Metabolites found in rats after exposure to HCB include pentachlorophenol, tetrachloro-1,4-hydroquinone, and diverse tetra- and tri-chlorophenols.^27^ Another major metabolic pathway is the conjugation of HCB with glutathione.^28^ This conjugate is further metabolized by cleavage of the glycine and glutamate residues resulting in pentachlorophenyl-N-acetyl-L-cysteine. This mercapturate can be eliminated unchanged via the urine^29,30^ or can be further metabolized by cleavage of the carbon-sulfur bond to produce pentachlorobenzenethiol, pentachlorothioanisol, tetrachloro-1,4-benzenedithiol, tetrachlorobenzenethiol, pentachlorobenzene, and other minor metabolites.^31,32^ Metabolism has been reported to differ in male and female rats with higher excretion of pentachlorophenol, tetrachloro-1,4-benzenedithiol, and pentachlorothiophenol in females.^33^

In male Sprague Dawley rats, HCB was predominately eliminated as the parent chemical in the feces (16% of dose administered).^34^ The whole-body half-life of HCB in male Wistar rats given 0.2 mg HCB via gavage was approximately 20 days.^35^ In male Sprague Dawley rats consuming 5% HCB in the diet for 8 weeks, the half-life was 24 days.^21^

A study by the National Toxicology Program (NTP) estimated toxicokinetic parameters of HCB in female Sprague Dawley rats (Appendix D). Rats were given a single intravenous (0.1 and 10 mg/kg) or gavage (0.03, 0.3, 30 mg/kg) dose. HCB was measured in whole blood, adipose tissue, liver, and lung over the course of 84 days. After intravenous administration, the systemic exposure parameters for HCB increased linearly with dose with a half-life of approximately 3 days. After oral administration, HCB was rapidly absorbed; peak blood concentrations were reached within 4 hours. The highest concentration of HCB was in the adipose tissue, followed by liver, then lung. Kinetics of HCB in blood following oral administration appeared nonlinear. The half-life of HCB in the blood was 23 days in the lowest dose group but decreased to 12 days at the two higher doses. Bioavailability exceeded 100% at all doses and decreased at the highest dose. Collectively, these data demonstrate potential saturation of absorption and elimination processes after oral administration and route differences in disposition of HCB.

Several physiologically based pharmacokinetic (PBPK) models are available for HCB. Yesair et al.^36^ developed the first HCB PBPK model that describes the pharmacokinetics of repeated exposure to HCB in adult male and female rats and in dams and their offspring. Freeman et al.^37^ and Lu et al.^38^ also developed PBPK models for HCB in rats.

### Humans

Absorption of inhaled HCB in humans is estimated to be minimal. Ingested HCB through foods, particularly fatty items, however, is estimated to be 85.4% absorbed when the blood of the ingesting individual contains no HCB.^39,40^ Net absorption appears to decrease with higher accumulation of HCB in tissues and/or blood.^39^ HCB distributes in humans depending on lipid solubility and lipid content of the tissues.^41-43^ As in experimental animals, HCB has been shown in humans to pass from the mother to the fetus or neonate through the placenta or breast milk.^44-47^

Metabolism of HCB in humans is not as well-documented. The rural village of Flix, Spain, surrounds an electrochemical plant that has been associated with high ambient air concentrations of HCB (35 ng/m^3^) for four decades. In this highly exposed human population (mean serum HCB concentrations of 39.8 ng/mL in Flix versus 4.13 ng/mL in Barcelona), high concentrations of pentachlorophenol and pentachlorobenzenethiol, a sulfur derivative, were detected in the urine.^48^ In samples obtained from patients in Germany, only the parent compound was detected in adipose tissue, whereas pentachlorophenol was found only in the urine.^49^

Similar to experimental animals, elimination of the parent chemical in humans is primarily through feces.^50^ Metabolites of HCB are excreted primarily through the urine. Pentachlorobenzenethiol concentrations in the urine of Flix residents in Spain correlated strongly with serum HCB concentrations, confirming that urinary excretion contains primarily metabolites of HCB. Given estimated daily elimination rates of HCB and its metabolites via urine and feces, the half-life of HCB was predicted to be approximately 6 years in this population.^50^ The PBPK model developed by Freeman et al.^37^ for rats was extrapolated to humans by incorporating human physiological parameters.^36^ This PBPK model predicted a half-life of 215 days (0.58 years) in a 15-year-old girl with exposure to 0.5–32 mg/kg/day for 15 weeks.

## Toxicity

### Experimental Animals

The oral median lethal dose (LD_50_) values for HCB in animals range from 1,700 mg/kg (cats) to 3,500–10,000 mg/kg (rats); LD_50_ values for mice, rabbits, and guinea pigs fall within that range.^1^ Reported effects of HCB include mainly immunological, hepatotoxicological, respiratory, and neurological effects. Short-term and subchronic oral exposure of rats to doses ranging from 30 to 250 mg/kg resulted in alterations in body weight, cutaneous lesions, tremors and other neurological signs, hepatomegaly, liver damage, and changes in porphyrin or heme metabolism.^1^ Biochemical alterations include induction of xenobiotic metabolizing enzymes including cytochrome P450 (CYP)1A1, CYP1A2, CYP2B, and glutathione-S-transferases and induction of thyroid hormone glucuronidation.^51^ HCB also altered circulating thyroid hormone levels and increased thyroid hormone catabolism. Interestingly, the no-observed-effect levels (NOELs) for both toxic and biochemical effects are of the same order of magnitude.^1^

In rats, the hepatic effects of HCB include increased liver weight, microsomal enzyme induction, hepatocellular hypertrophy, cytoplasmic vacuolation, fatty degeneration, and biliary hyperplasia.^3^ HCB induces CYP1A, CYP2B, and CYP3A isoforms in hepatic tissue. These data suggest that HCB activates the aryl hydrocarbon (Ah) receptor, the constitutive androstane receptor, and/or the pregnane X receptor. HCB does bind the Ah receptor, although it is approximately 10,000 times less potent than 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD).^52^ Hepatic porphyria typically occurs in rats, provided the exposure is of sufficient dose and duration. Using CYP1A2 knockout mice, Sinclair et al.^53^ demonstrated that induction of porphyria by HCB requires CYP1A2 expression.

Several studies in rats have reported that oral exposure to HCB produces pulmonary lesions. Low-dose effects typically include hypertrophy and proliferation of the endothelial cells lining the pulmonary venules and intra-alveolar accumulation of foamy-looking macrophages. These pulmonary lesions have occurred in both sexes of six different strains of rats at doses as low as 3 mg/kg.^54-59^ At doses between 25 and 50 mg/kg, pulmonary lesions in rats include inflammation, edema, and decreased respiratory function.^54,59^

Several reports explore the endocrine-disrupting effects of HCB. High doses of HCB alter ovarian function in primates and rodents. In cycling female rhesus monkeys, HCB reduced circulating concentrations of estradiol, although only one of the four animals failed to ovulate.^60^ In contrast, HCB did not alter circulating concentrations of estradiol in cycling cynomolgus monkeys but did result in lower serum progesterone concentrations during the luteal phase.^61,62^ In superovulated female rats, animals treated with HCB had higher serum progesterone compared to animals that were not treated with HCB.^63^ HCB also decreases circulating thyroid hormones following repeated exposures in rats^64-66^ and hamsters.^67^ These effects appear related to increased glucuronidation of thyroxine and interactions with serum thyroid hormone transport proteins.

HCB has immunosuppressive effects in mice and immunostimulatory effects in rats and dogs (reviewed in IPCS,^1^ Vos et al.^68^). Male and female rats exposed to HCB had higher spleen and lymph node weights. The higher spleen weights were associated with increased incidences of extramedullary hematopoiesis and hyperplasia of the splenic B-cells. Lymph nodes had higher numbers of high endothelial venules. These histological changes were not associated with changes in cell-mediated immunity as evaluated by functional assessments of macrophages using the Listeria monocytogenes mortality assay, skin graft rejection challenges, and delayed-type hypersensitivity. HCB stimulated humoral immunity to the thymus-dependent antigen, tetanus toxoid, but did not alter the thymus-independent immunoglobulin M (IgM) response to lipopolysaccharide.

### Humans

Much of what is known about the health effects of HCB in humans derives from an accidental mass poisoning in Turkey from 1955 to 1959 where as many as 3,000–5,000 people consumed HCB-treated wheat grain that was ground into flour and made into bread.^1^ Estimated intake of HCB in this population was 50–200 mg/day.^69^ Observed effects included mortality (10%), porphyria cutanea tarda, other skin lesions (erythema, bullae), ulcerations and resultant scarring, friable skin, hyperpigmentation, hypertrichosis, enlarged liver, weight loss, enlargement of lymph nodes, neurological effects, osteoporosis of the extremities, and deformation of the fingers (arthritis). Goiter was present in 27% of exposed men and 60% of exposed women compared to an average of 5% among unexposed individuals in this region. Exposed infants developed pink cutaneous lesions (pembe yara or pink sore), fever, diarrhea, vomiting, weakness, convulsions, enlarged liver, and progressive wasting. At least 95% of these children died within a year of birth, and in many villages no children between the ages of 2 and 5 years survived from 1955 to 1960.^1^ In contrast, the Flix, Spain, cohort, which was exposed to lower concentrations, showed few associations between HCB exposure and adverse noncancer effects.^46,70,71^

## Reproductive and Developmental Toxicity

### Experimental Animals

In Sprague Dawley rats, perinatal exposure to 100 ppb HCB in feed (equating to an approximate consumption of 6 μg HCB/kg/day by the dams) resulted in decreased pup body weights.^24^ Arnold et al.^72^ exposed rats to diets containing 0, 0.32, 1.6, 8.0, or 40 ppm of HCB for 90 days prior to mating until weaning. No effects on reproductive parameters were observed in the F_0_ generation; however, there were decreases in pup body weight in the top dose group. After weaning, F_1_ animals were exposed to the same concentration of HCB as their parents and examined after 130 weeks. No HCB-induced adverse effects were reported in the 0, 0.32, and 1.6 ppm F_1_ groups. The 8.0 and 40 ppm groups had increased incidences of hepatic centrilobular basophilic chromogenesis. Males in the 40 ppm group also had severe chronic nephrosis. No reproductive or developmental effects were examined in the F_1_ animals.

A four-generation study was conducted in Sprague Dawley rats fed diets containing 0, 10, 20, 40, 80, 160, 320, or 640 ppm HCB throughout mating, gestation, and lactation. The two highest exposure concentrations caused deaths in F_0_ dams before the first deliveries and reduced the fertility index. Animals consuming diets with concentrations of ≥160 ppm HCB had a reduced litter size, increased number of stillbirths, and lower pup survival. Similar effects were seen at 80 ppm after the first two generations, and 40 ppm produced enlarged livers and higher aniline hydroxylase activity in the F_1a_ and F_3a_ pups. The dietary concentration of 20 ppm (~1–2 mg/kg/day) was designated as the NOEL.^73^

CD-1 mice administered 100 mg/kg by gavage on gestation days (GD) 7–16 had significantly increased incidences of abnormal fetuses per litter and one case of renal agenesis.^74^ Some pups were born with cleft palates, but they all occurred in one litter. Increased maternal liver-to-body weight ratios and decreased fetal body weights also occurred.

Andrews and Courtney^75^ administered 0, 10, or 50 mg/kg HCB to CD-1 female mice on GD 6–16. In exposed pups, enlarged kidneys and hydronephrosis were observed on postnatal day (PND) 15. Similar studies in CD rats showed enlarged kidneys on PND 5 in dams administered 10 mg/kg on GD 15–20 and a significant increase in the kidney:body weight ratio and the liver:body weight ratio in HCB-exposed pups on PNDs 5, 10, and 20.

Goldey and Taylor^23^ reported effects on neurobehavioral development in the offspring of female rats administered 2.5 or 25 mg/kg for 4 consecutive days (10 and 100 mg/kg total), 2 weeks prior to breeding. Exposed females were bred with nonexposed males. Pups in both exposed groups were hyperactive (determined by tests of negative geotaxic reflex, olfactory discrimination, and exploratory locomotor activity) at PND 6–20. Pups from the 25 mg/kg dose group showed reduced acoustic startle response at PND 23 but an increased response at PND 90. These doses did not affect learning (as determined by the swim T-maze test) or motor activity in older offspring, nor maternal or fetal body weights, length of gestation, number of pups per litter, or number of days to eye opening.

Lilenthal et al.^76^ also noted neurotoxic effects in rats. Female rats were fed diets containing 0, 4, 8, or 16 ppm HCB for 90 days prior to mating and through lactation. In contrast to Goldey and Taylor,^23^ no significant differences were noted on PND 21 in open-field activity or active avoidance learning on PND 90. Training of operant behavior started at PND 150 for the control, 8 ppm, and 16 ppm groups. Dose-dependent reductions occurred in the post-reinforcement pause (i.e., time between reinforcement and the first reaction emitted). In addition, the efficiency of reinforcement was decreased in a dose-dependent manner.

Vos et al.^77^ evaluated the effects of HCB on the developing immune system in Wistar rats exposed to HCB in the diet starting on days 1–3 of pregnancy. Dams and pups were maintained on this diet throughout the study. The immune system was evaluated in the pups at 5 weeks of age. Resistance to Listeria monocytogenes and Trichinella sprialis was suppressed in the pups. In contrast, HCB enhanced the thymus-dependent antibody response to tetanus toxoid by over 16-fold. Vos et al. concluded that HCB enhances humoral immunity and suppresses cellular immunity after developmental exposures.

### Humans

In the Turkish cohort, at least 95% of the children died within a year of birth, and in many villages no children between the ages of 2 and 5 years survived from 1955 to 1960.^1^ In the Flix cohort, which was exposed to lower concentrations of HCB, HCB exposure was not associated with developmental neurobehavioral outcomes^78^ or thyroid status in neonates.^79^ Higher exposure concentrations of HCB, however, were associated with premature birth, short length for gestational age, and a decrease in crown-heel length.^80^ An epidemiology study published in 2008 suggested an association between perinatal HCB exposures and increases in body mass index and weight.^81^

## Carcinogenicity

### Experimental Animals

Syrian golden hamsters developed liver cell tumors (hepatoma) in both males and females after dietary exposure to HCB.^82^ In addition, these investigators found increased incidences of hemangioendothelioma in both sexes and adenoma of the thyroid gland in males. In female mice, the incidences of hepatoma were increased after dietary exposure to 100 and 200 ppm HCB for 120 weeks.^83^ In a two-generation study in Sprague Dawley rats, the F_1_ females had increased incidences of neoplastic liver nodules and adrenal gland pheochromocytoma.^72^ Males had increased incidences of parathyroid gland adenoma in the same experimental setup. In a 2-year study in Sprague Dawley rats, there were increased incidences of hepatoma, hemangiomas, hepatocellular carcinomas, bile duct carcinomas, and renal cell adenoma after consumption of 75 or 150 ppm HCB in the diet.^84^ Females had increased incidences of hepatocellular carcinoma and bile duct adenoma/carcinoma, in addition to increased incidences of adrenal cortical adenoma and pheochromocytoma.

### Humans

HCB is reasonably anticipated to be a human carcinogen.^85^ The International Agency for Research on Cancer concluded that there is inadequate evidence in humans but sufficient evidence in experimental animals for the carcinogenicity of HCB.^86,87^ EPA assigned HCB as a probable human carcinogen (Group B2) on the basis of findings of tumors in the liver, thyroid, and kidney in three rodent species.^88^ Increased incidences of soft-tissue sarcoma and thyroid gland neoplasms were observed in men exposed to HCB in ambient air in the Flix cohort.^89^ In the Turkish cohort, there was no evidence of increased cancer incidence.^1^ In both these analyses, however, researchers followed up with only a small fraction of the exposed population.

## Genetic Toxicity

Reviews of the literature on the genotoxicity of HCB^3,90,91^ indicated that assays for mutagenic activity of HCB in bacterial or mammalian cell systems were generally negative, with some exceptions. There was some evidence that HCB might induce DNA or chromosomal damage, but the results were inconsistent across the assays.

HCB (up to 1,000 μg/plate) was not mutagenic in Salmonella typhimurium strains TA98, TA100, TA1535, or TA1537 or in Escherichia coli WP2 in the presence or absence of microsomal activation (S9).^92^ These results are consistent with previously reported negative results in several S. typhimurium strains treated with concentrations of HCB up to 10,000 μg/plate, with and without S9.^93^ However, one study reports mutagenic activity of HCB at a lower dose, 50 μg/plate, in strain TA98 exposed in the presence of S9; without S9, no mutagenic activity was observed at HCB concentrations up to 100 μg/plate.^94^ HCB, in the absence of S9, induced 8-azaguanine resistance but did not induce ouabain resistance in Chinese hamster V-79 cells.^95^

HCB did not induce micronuclei, biomarkers of chromosomal damage, in cultured human lymphocytes when tested without exogenous metabolic activation at concentrations of up to 0.1 mM.^96^ In contrast, Canonero et al.^97^ reported significant increases in both DNA strand breaks (measured by the comet assay) and micronuclei in primary cultures of human hepatocytes exposed in vitro with concentrations of HCB up to 0.56 mM. Testing HCB under the same conditions and concentration range in rat hepatocytes did not induce DNA strand breaks but did induce a significant increase in micronuclei. Positive results in tests for induction of DNA damage by HCB (1 μg/mL) were also reported in National Institutes of Health 3T3 mouse embryonic and WS1 human primary embryonic fibroblast cells.^98^ Despite the observations of induced DNA damage and micronuclei, no chromosomal aberrations were detected in cultured human peripheral blood lymphocytes after exposure to HCB up to 0.1 mM.^92^ Results of a study designed to evaluate HCB-induced DNA damage in an E. coli test system (differential growth in wild-type and DNA repair-deficient strains) were negative.^92^

In vivo, HCB (doses of up to 221 mg/kg in corn oil) failed to induce dominant lethal mutations in germ cells of male rats (strain not specified) treated once daily by gavage for 5 days.^99^ In addition, no dominant lethal mutations were observed in male Wistar rats that were administered doses up to 60 mg/kg for 10 days.^100^ HCB, at a dose of 25 mg/kg, bound to rat liver DNA, with or without pretreatment with phenobarbital.^94^

## Role of the Aryl Hydrocarbon Receptor in the Toxicity of Hexachlorobenzene

HCB and TCDD share many chemical properties and have similar biological effects. They are both planar persistent organic pollutants. Like TCDD, HCB binds to the Ah receptor and induces some of the same toxicities as TCDD induces. HCB is also a rodent liver tumor promoter that induces CYP1A enzymes^101^ in rats and mice.^52,102^ Studies in C57BL/6J mice congenic at the Ah locus indicate that mice with some expression of the Ah receptor develop porphyria earlier and to a much greater extent than mice that do not express the receptor.^103^ Hahn and colleagues determined that HCB is a weak Ah receptor agonist, suggesting that some of the toxicity of HCB is mediated through its interaction with the Ah receptor. HCB also exerts effects independent of the Ah receptor. For example, HCB induces CYP2B enzymes,^101^ which are typically mediated through interactions with the constitutive androstane receptor. In a mammary gland tumor promotion study, HCB exposure alone did not increase the incidence and multiplicity of tumors, but the combination of HCB and N-nitroso-N-methylurea (NMU) increased the incidence and multiplicity of mammary gland tumors compared to animals treated by NMU alone.^104^ The mammary gland effects appear to be mediated through activation of c-SRC and estrogen receptor and are independent of the Ah receptor.^105^

## Study Rationale

HCB is of concern due to widespread human exposure and its structural resemblance to a well-characterized toxicant, TCDD. Indeed, in experimental animals, HCB induces some biological effects similar to TCDD. HCB was proposed for study as part of the toxic equivalency factor (TEF) initiative to generate suitable data to establish relative potency factors (RPFs) for the class of chemicals similar to TCDD, that is, dioxin-like compounds or dioxins. The rationale and overview of the TEF studies is presented in the NTP technical report for 3,3’,4,4’,5-pentachlorobiphenyl (PCB 126).^106^ Briefly, the TEF methodology is a relative potency scheme that ranks the activity of a compound relative to TCDD. This method allows for the estimation of the dioxin-like activity of a mixture of chemicals with the assumption that the chemicals bind to the Ah receptor, a common mechanism of action. An application of the TEF methodology includes the prediction of cancer risk, particularly of chemical (dioxins) mixtures. The dioxin TEF studies were conducted at NTP in female Sprague Dawley rats and were predicated on prior observations by Kociba et al.^107^ of the carcinogenicity of TCDD in Spartan Sprague Dawley rats. The primary goal of the present study was to generate data that would enable a decision on whether to include HCB in the TEF studies at NTP. RPFs for various toxicological and biochemical endpoints after HCB exposure were generated and compared to TCDD data generated in the TEF studies.^108^

Human exposure to HCB is predominately from the diet through consumption of contaminated foods. Because the oral route is the most likely means of exposure, HCB was administered by oral gavage in the current study. Oral gavage was also the route of exposure for the TCDD TEF studies.^108^