# Appendix F Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NTP-DATA-TOX-77.

## F.1 Short-Term

### F.1.1 Three-Month Study Tables – Rats

E03 – Initial and Current Body Weights

E40 – Growth Curves

E41 – Mean Body Weights and Survival Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Sites (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

PA45 – Hepatic Cell Proliferation Data

PA48 – Summary of Tissue Concentration

PA49 – Summary of Cytochrome Activity

R07 – Hormone Summary

### F.1.2 Three-Month Individual Animal Data – Rats

Female Individual Animal Body Weight Data

Female Individual Animal Clinical Observations

Female Individual Animal Neoplastic Pathology Data

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Individual Animal Cytochrome Activity Data

Individual Animal Hormone Data

Individual Animal Liver Special Studies Data

Individual Animal Organ Weight Data

Individual Animal Tissue Concentration Data

## F.2 Toxicokinetics

### F.2.1 TK Parameter Data

TK Hexachlorobenzene S0654 S0811 Remodeled IV Gav Rat Female

### F.2.2 Individual Animal Data

TKS Hexachlorobenzene 2001 S0654 Individual Animal Data

TKS Hexachlorobenzene 2003 S0811 Individual Animal Data