# Appendix E Genetic Toxicology

## E.1 Bacterial Mutagenicity Test Protocol

Testing was performed as reported by Haworth et al.^93^ Hexachlorobenzene (HCB) was sent to the laboratory as a coded aliquot from Radian Corporation (Austin, TX). It was incubated with the Salmonella typhimurium tester strains TA98, TA100, TA1535, and TA1537, in either buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague Dawley rat or Syrian hamster liver) for 20 minutes at 37°C. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted after 2 days of incubation at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and of five doses of HCB. In the absence of toxicity, the high dose was limited by experimental design to 10,000 μg/plate. All trials were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, reproducible, or of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. No minimum percentage or fold-increase is required for a chemical to be judged positive or weakly positive.

## E.2 Results

HCB (100 to 10,000 μg/plate) was not mutagenic in S. typhimurium strains TA98, TA100, TA1535, or TA1537 with or without rat or hamster liver S9 activation enzymes (Table E-1).

Table E-1 Mutagenicity of Hexachlorobenzene in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% Hamster S9 | With 10% Hamster S9 | With 10% Rat S9 | With 10% Rat S9
TA100
| 0 | 81 ± 8 | 91 ± 3 | 96 ± 10 | 93 ± 6 | 107 ± 3 | 88 ± 7
| 100 | 88 ± 6 | 86 ± 7 | 92 ± 5 | 107 ± 4 | 113 ± 6 | 101 ± 13
| 333.3 | 83 ± 5 | 86 ± 4 | 92 ± 4 | 90 ± 5 | 93 ± 5 | 87 ± 7
| 1,000 | 63 ± 7^b^ | 68 ± 4^b^ | 82 ± 5^b^ | 105 ± 3 | 83 ± 5^b^ | 77 ± 7^b^
| 3,333 | 75 ± 7^b^ | 88 ± 6^b^ | 86 ± 8^b^ | 93 ± 4 | 103 ± 12^b^ | 97 ± 9^b^
| 10,000 | 72 ± 8^b^ | 87 ± 8^b^ | 87 ± 2^b^ | 97 ± 2 | 92 ± 2^b^ | 99 ± 2^b^
Trial Summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive Control^c^ | | 376 ± 18 | 500 ± 11 | 1,238 ± 91 | 290 ± 21 | 826 ± 36 | 1,066 ± 12
TA1535
| 0 | 18 ± 4 | 8 ± 1 | 9 ± 1 | 12 ± 3 | 11 ± 3 | 5 ± 2
| 100 | 22 ± 3 | 10 ± 1 | 7 ± 2 | 5 ± 1 | 8 ± 0 | 6 ± 1
| 333.3 | 15 ± 1 | 9 ± 1 | 5 ± 1 | 6 ± 3 | 10 ± 2 | 6 ± 1
| 1,000 | 20 ± 1^b^ | 12 ± 2^b^ | 9 ± 1^b^ | 8 ± 3^b^ | 9 ± 3^b^ | 4 ± 1^b^
| 3,333 | 17 ± 4^b^ | 9 ± 1^b^ | 13 ± 3^b^ | 8 ± 1^b^ | 9 ± 2^b^ | 8 ± 1^b^
| 10,000 | 13 ± 2^b^ | 11 ± 3^b^ | 10 ± 1^b^ | 7 ± 2^b^ | 9 ± 0^b^ | 5 ± 1^b^
Trial Summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive Control^c^ | | 300 ± 21 | 337 ± 23 | 326 ± 21 | 186 ± 13 | 355 ± 11 | 387 ± 26
TA1537
| 0 | 6 ± 1 | 6 ± 0 | 10 ± 2 | 5 ± 1 | 15 ± 0 | 6 ± 1
| 100 | 7 ± 2 | 8 ± 2 | 16 ± 3 | 9 ± 2 | 21 ± 2 | 7 ± 1
| 333.3 | 12 ± 2 | 4 ± 0 | 16 ± 3 | 10 ± 3 | 17 ± 2 | 7 ± 1
| 1,000 | 8 ± 1^b^ | 6 ± 2^b^ | 23 ± 4^b^ | 10 ± 2^b^ | 22 ± 5^b^ | 8 ± 1^b^
| 3,333 | 10 ± 2^b^ | 5 ± 2^b^ | 15 ± 3^b^ | 8 ± 1^b^ | 21 ± 2^b^ | 9 ± 1^b^
| 10,000 | 11 ± 1^b^ | 7 ± 2^b^ | 15 ± 0^b^ | 9 ± 1^b^ | 18 ± 2^b^ | 7 ± 1^b^
Trial Summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive Control^c^ | | 245 ± 43 | 258 ± 17 | 487 ± 35 | 362 ± 20 | 297 ± 29 | 461 ± 16
TA98
| 0 | 19 ± 1 | 14 ± 3 | 29 ± 2 | 22 ± 2 | 41 ± 2 | 22 ± 3
| 100 | 23 ± 4 | 15 ± 2 | 34 ± 3 | 22 ± 1 | 41 ± 1 | 26 ± 2
| 333.3 | 23 ± 1 | 15 ± 1 | 32 ± 7 | 20 ± 2 | 35 ± 3 | 25 ± 2
| 1,000 | 19 ± 1^b^ | 15 ± 2^b^ | 34 ± 3^b^ | 24 ± 3^b^ | 41 ± 4^b^ | 23 ± 4^b^
| 3,333 | 20 ± 4^b^ | 16 ± 0^b^ | 36 ± 4^b^ | 16 ± 1^b^ | 30 ± 1^b^ | 23 ± 1^b^
| 10,000 | 23 ± 2^b^ | 21 ± 2^b^ | 38 ± 1^b^ | 19 ± 4^b^ | 37 ± 2^b^ | 19 ± 2^b^
Trial Summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive Control^c^ | | 655 ± 70 | 693 ± 39 | 198 ± 10 | 199 ± 8 | 542 ± 13 | 787 ± 53

^a^ Data are presented as revertants/plate (mean ± standard error) from three plates. Study was performed at SRI International. The detailed protocol and these data are presented by Haworth et al.^93^; 0 μg/plate was the solvent control.

^b^ Precipitate on plate.

^c^ The positive controls in the absence of metabolic activation were sodium azide (TA100 and TA1535), 9-aminoacridine (TA1537), and 4-nitro-o-phenylenediamine (TA98). The positive control for metabolic activation with all strains was 2-aminoanthracene.