# Appendix D Toxicokinetic Data

## D.1 Introduction

Due to the paucity of toxicity data, the National Toxicology Program evaluated the toxicity of hexachlorobenzene (HCB). To support the toxicity studies, toxicokinetic evaluations were conducted in female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats administered a single dose of HCB by oral gavage (30, 300, and 30,000 μg/kg) or intravenously (IV; 100 and 1,000 μg/kg).

## D.2 Materials and Methods

### D.2.1 Chemicals and Dose Formulation

HCB was obtained from Aldrich Chemical Company, Milwaukee, WI (Lot No. 08526EF). The chemical identity was confirmed using infrared spectroscopy, ^13^C NMR, and gas chromatography/mass spectrometry (GC/MS). The purity was determined to be >99% by GC with flame ionization detection. Corn oil, the oral dose vehicle, was obtained from Spectrum Quality Products, Inc. (Gardena, CA; Lot No. NL0405 or OJ0240). The IV dose formulation vehicle was a homogenous solution (5:0.15:0.14:95 v/w/w/v) of corn oil, cholic acid (Lot No. 128H0154; Sigma, St. Louis, MO), lecithin (Lot No. 49H8018; Sigma, St. Louis, MO), and Ringer’s solution (Lot No. C437210; Baxter, Deerfield, IL).

Oral dose formulations of HCB (12 µg HCB/mL, 120 µg HCB/mL, and 12 mg HCB/mL) were prepared in corn oil. IV dose formulations (25 and 250 µg/mL) were prepared in the IV formulation vehicle. Formulations were analyzed by a validated GC method using a Hewlett-Packard Model 6890 with electron capture detection (ECD) (linear range 50 to 497 ng/mL; r ≥ 0.99; accuracy: ≤4.4%, estimated as relative error; precision: ≤0.7%, estimated as relative standard deviation. All oral and IV formulations were within 10% of the target concentration. Prior to study initiation, stability (≤10% of day 0) of both oral and IV formulations were confirmed for up to 35 days when stored at ambient or refrigerated conditions.

### D.2.2 Animals

Two studies (one evaluating 30 and 3,000 µg/kg gavage doses, another evaluating IV doses and 300 µg/kg gavage dose) were conducted at MRIGlobal (Kansas City, MO) in accordance with the guidelines of the U.S. Department of Agriculture through the Animal Welfare Act (Public Law 89-544 and its subsequent amendments), Guide for the Care and Use of Laboratory Animals, DHHS Publication No. (NIH) 86-23 (Revised, 1985) and MRIGlobal Standard Operating Procedure. Animals were housed in facilities that are fully accredited by AAALAC International. Nine-week-old female Sprague Dawley rats were received from Charles River (Portage, MI) and randomized into dose groups. Rats were housed in environmentally controlled rooms, with at least 10 room air exchanges per hour, a 12-hour light/dark cycle per day, room temperature of 66°F–83°F, and relative humidity from 28% to 77%. Animals had access to NTP-2000 meal feed (Ziegler Brothers, Inc., Gardeners, PA) and water from the public water supply ad libitum.

Body weights were recorded for all animals prior to the start of the study, on the day of dosing prior to dose administration, and prior to euthanasia. Single IV doses were administered at 100 and 1,000 µg/kg in a volume of 4.0 mL/kg via the lateral tail vein. Oral doses were administered at 30, 300, and 30,000 µg/kg in 2.5 mL/kg via oral gavage. Animals were 21 weeks of age at time of dosing.

### D.2.3 Sample Collection and Analysis

Following dose administration, whole blood samples were collected into heparinized tubes at 5-6 time points. Table D-1 shows the study design and time points for blood and tissue collections. Non-terminal blood collections (n = 10/time point, 2 mL) were collected via the retroorbital sinus under light CO_2_ anesthesia. For tissue collection time points, animals (n = 5/time point) were euthanized by exsanguination via the abdominal aorta under Metofane (Mallinckrodt Veterinary, Mundelein, IL) anesthesia; whole blood, liver, lung, and mesenteric adipose were collected. Organs were weighed at the time of collection. All samples were stored at −20°C until analysis.

Table D-1 Study Design for the Oral and Intravenous Toxicokinetic Studies in Female Rats

Study | Route of Administration and Dose | Blood Collection Time Points^a^ | Tissue Collection Time Points^b^
1 | Gavage: 30 and 30,000 µg/kg | 0.5, 1, 12, 120, 240 | 72, 168, 336, 672, 1,008, 1,344, 1,680, 2,016 (3, 7, 14, 28, 42, 56, 70, 84)
2 | IV:100 and 1,000 µg/kg | 0.25, 0.5, 1, 12, 120, 240 | 48, 72, 168, 336, 672, 1,008, 1,344, 1,680, 2,016 (2, 3, 7, 14, 28, 42, 56, 70, 84)
2 | Gavage: 300 µg/kg | 0.5, 1, 12, 120, 240 | 72, 168, 336, 672, 1,008, 1,344, 1,680, 2,016 (3, 7, 14, 28, 42, 56, 70, 84)

IV = intravenous.

^a^ n = 10; data are presented in hours.

^b^ n = 5; data are presented in hours (days).

All samples were analyzed using validated analytical methods (Table D-3, Table D-4, Table D-5, Table D-6). 100 μL of acetonitrile was added to 100 μL aliquots of blood in individual vials. Samples were mixed for approximately 20 seconds, followed by the addition of 100 μL of the internal standard solution (isodrin, approximately 2 μg/mL in hexane) and 900 μL of hexane. The contents of each vial were mixed for approximately 40 seconds. Vials were centrifuged at approximately 800 g for approximately 5 minutes and the supernatant was collected for analysis. Liver and lung samples (0.1–0.4 g of tissue) were prepared similarly to blood except that tissues were homogenized using Polytron homogenizer prior to protein precipitation with approximately 0.5 mL acetonitrile. Adipose tissue samples were prepared by homogenizing 0.1–0.4 g of adipose tissue and then adding 1 mL hexane. The homogenized adipose sample was transferred to an individual solid phase extraction cartridge and eluted with approximately 20 mL hexane. The hexane eluate was collected and diluted to 25 mL with hexane, and 1 mL was combined with 0.5 mL internal standard solution (~0.1–1 µg/mL aldrin in hexane) for analysis. High-dose samples were diluted with control matrix into the analytical method range (20–5,000 ng/mL) prior to extraction when necessary. Standard curves and blanks were prepared with each sample set.

Blood, adipose, and lung samples, standards, and blanks were analyzed using a Hewlett-Packard/Agilent 6890 GC with an ECD detector. Analyte separation was achieved on a Restek RTX-5 column (60 m, 0.25 mm internal diameter [I.D.], 0.25 µM film thickness or 30 m, 0.53 mm I.D, 0.15 µm film thickness). For analysis of samples, the oven temperature program was 100°C (2-minute hold), then 50°C/minute to 200°C (1-minute hold), then 4°C/minute to 300°C. For analysis of adipose in the high-dose samples, the oven temperature program was 180°C (5-minute hold), then ramped at 5°C/minute to 275°C (5-minute hold). Liver, lung, and blood samples, standards, and blanks were analyzed using a Fisons 8030 GC with MD800-F MS detector with a J & W DB-5 column (30 m, 0.32 mm I.D., 1 µm film thickness) and an oven program of 70°C (2-minute hold), ramped at 50°C/minute to 200°C (1-minute hold), then 4°C/minute to 300°C.

### D.2.4 Toxicokinetic Analysis

WinNonlin (Version 8, Certara, Princeton, NJ) was used for toxicokinetic analysis. Blood HCB concentration versus time profiles utilizing all data points (5 or 10 rats per time point) were analyzed using various compartmental models. For each compartmental model, data sets were analyzed with and without weighting. The model and the weighing factor that resulted in the best goodness of fit was selected as the final model. On this basis, a two-compartment model with bolus input, first order output, and 1/y^2^ weighting was used for the IV data (equation 1), and a two-compartment model with first order input, first order output, and 1/y^2^ weighting was used for gavage data (equation 2). The kinetic parameters estimated are listed and defined in Table D-2. Tissue concentration versus time data were evaluated using noncompartmental analysis (NCA) with each data point representing the mean of five rats per dose group. Only data that were at or above the limit of detection were used in the calculations.

C_(t)_ = Ae^-αt^ + Be^-βt^ [Equation 1]

C_(t)_ = Ae^-αt^ + Be^-βt^ + Ce^-k^_01_^t^ [Equation 2]

Bioavailability following gavage administration was estimated using equation 3:

F% = [AUC_(gavage)_/Dose_(gavage)_]/[AUC_(IV)_/Dose_(IV)_] × 100 [Equation 3]

Table D-2 Glossary of Terms

Alpha Half-life | Half-life for the Alpha Phase
AUC | Area under the curve from the time of dosing extrapolated to infinity
AUC/Dose | Area under the curve adjusted for dose
Beta Half-life | Half-life for the beta phase
C_0_ | Concentration at time zero
C_0_/Dose | Concentration at time zero adjusted for dose
CL_1_ and CL_1__F | Clearance for the central compartment (IV and oral)
CL_2_ and CL_2__F | Clearance for the peripheral compartment (IV and oral)
C_max_ | Maximum concentration
F | Bioavailability
K_10_ | Elimination rate constant
lK_10_ Half-life | Half-life of elimination
K_12_ and K_21_ | Distribution rate constants
MRT | Mean residence time
T_max_ | Time to reach maximum concentration
V_1_ and V_1__F | Volume of distribution in the central compartment (IV and oral)
V_2_ and V_2__F | Volume of distribution in the peripheral compartment (IV and oral)
V_ss_ | Volume of distribution at steady state

IV = intravenous.

## D.3 Results

No animals were found dead or moribund due to toxicity or any dose-related clinical signs observed following IV or gavage administration of HCB at any dose level.

### D.3.1 Analytical Method Validation

Analytical methods for HCB were validated and analyte stability was evaluated in all matrices (Table D-3, Table D-4, Table D-5, Table D-6). The analytical method was suitable for quantitation of HCB in all matrices (r ≥ 0.99; precision ≤5.7%; accuracy ≤ ±19.3%). HCB was stable in all matrices at −20°C for up to 21 days.

Table D-3 Analytical Method Validation for Hexachlorobenzene in Blood

| Matrix Concentration Range (ng/mL)
| 1–400 | 20–5,000
Analytical Instrument | Fisons 8030 GC with MD800-F MS detector | Agilent 6890 GC with EC detector
Validation Parameters
Limits (ng/mL or ng/g)
Limit of detection | 0.5 | 2.2
Experimental limit of quantitation | 4 | 20
Linearity (R^2^) | ≥0.99 | ≥0.99
Accuracy (% RE) | ≤ ±19.3 | ≤ ±8.5
Precision (% RSD) | ≤5.7 | ≤3.6
Mean Recovery^a^ (%) | ≥57.3 | ≥84.5
Stability of Hexachlorobenzene at 20°C for up to 21 Days^b^
% of Target Concentration | ≥91.7
% RE | ≤ ±3.6

GC = gas chromatography; MS = mass spectrometry; EC = electron capture; RE = relative error; RSD = relative standard deviation.

^a^ Relative to corresponding solvent standards.

^b^ Concentration tested was 1 µg/mL.

Table D-4 Analytical Method Validation for Hexachlorobenzene in Adipose

| Matrix Concentration Range (ng/g)
| 50–385 | 350–2,300
Analytical Instrument | Agilent 6890 GC with EC detector | Agilent 6890 GC with EC detector
Validation Parameters
Limits (ng/mL or ng/g)
Limit of detection | 5.2 | 5.2
Experimental limit of quantitation | 50 | 50
Linearity (R^2^) | ≥0.99 | ≥0.99
Accuracy (% RE) | ≤ ±9.1 | ≤ ±8.7
Precision (% RSD) | ≤4.5 | ≤4.5
Recovery^a^ (%) | ≥92.0 | ≥93.1
Stability of Hexachlorobenzene at 20°C for up to 21 Days^b^
% of Target Concentration | ≥90.9
% RE | ≤ ±8.4

GC = gas chromatography; EC = electron capture; RE = relative error; RSD = relative standard deviation.

^a^ Relative to corresponding solvent standards.

^b^ Concentration tested was 191.1 µg/g.

Table D-5 Analytical Method Validation for Hexachlorobenzene in Liver

| Matrix Concentration Range (ng/g)
| 1–10,000
Analytical Instrument | Fisons 8030 GC with MD800-F MS detector
Validation Parameters
Limits (ng/mL or ng/g)
Limit of detection | 0.05
Experimental limit of quantitation | 1
Linearity (R^2^) | ≥0.99
Accuracy (% RE) | ≤ ±11.4
Precision (% RSD) | ≤5.4
Recovery^a^ (%) | ≥81.4
Stability of Hexachlorobenzene at 20°C for up to 21 Days^b^
% of Target Concentration | ≥89.8
% RE | ≤ ±6.2

GC = gas chromatography; MS = mass spectrometry; RE = relative error; RSD = relative standard deviation.

^a^ Relative to corresponding solvent standards.

^b^ Concentration tested was 0.5 µg/g.

Table D-6 Analytical Method Validation for Hexachlorobenzene in Lung

| Matrix Concentration Range (ng/g)
| 1–10,000 | 7–360
Analytical Instrument | Fisons 8030 GC with MD800-F MS detector | Agilent 6890 GC with EC detector
Validation Parameters
Limits (ng/mL or ng/g)
Limit of detection | 0.05 | 0.5
Experimental limit of quantitation | 1.3 | 7.2
Linearity (R^2^) | ≥0.99 | ≥0.99
Accuracy (% RE) | ≤ ±9.9 | ≤ ±3.4
Precision (% RSD) | ≤2.7 | ≤2.3
Recovery^a^ (%) | ≥95.1 | ≥94.5
Stability of Hexachlorobenzene at 20°C for up to 21 Days^b^
% of Target Concentration | ≥95.5
% RE | ≤ ±4.8

GC = gas chromatography; MS = mass spectrometry; EC = electron capture; RE = relative error; RSD = relative standard deviation.

^a^ Relative to corresponding solvent standards.

^b^ Concentration tested was 0.5 µg/g.

### D.3.2 Blood Toxicokinetics of Hexachlorobenzene

HCB concentrations in blood were at or above the limit of detection at all time points for all doses. After IV and gavage administration, concentrations of HCB in the blood over time were best fit with a two-compartment model with first order absorption and/or elimination (Figure D-1 and Figure D-2). Following IV administration, the concentration at time 0 (C_0_) and area under the curve (AUC) increased proportionally to the dose administered (Table D-7). The volume of distribution to the second compartment (V_2_; 12,700–12,900 mL/kg) exceeded the estimated volume of aqueous body volume in rats (668 mL/kg), suggesting distribution of HCB into tissues. The elimination half-life (K_10_ half-life) in blood was similar for both doses (70.5–80.9 hours).

Figure D-1

Blood Concentrations versus Time Profiles of Hexachlorobenzene after a Single Intravenous Administration of a 100 (A) or 1,000 (B) µg/kg Dose in Female Rats

A two-compartmental model with bolus input, first order output, and 1/y^2^ weighting was used to fit the data.

Table D-7 Plasma Toxicokinetic Parameters of Hexachlorobenzene Following Single Intravenous Administration in Female Rats^a^

Parameter^b^ | Dose
Parameter^b^ | 100 µg/kg | 1,000 µg/kg
C_0_ (ng/mL) | 127 (11) | 1,490 (120)
C_0_/Dose (ng/mL/µg/kg) | 1.27 (0.11) | 1.49 (0.12)
Alpha Half-life (hr) | 0.783 (0.065) | 0.724 (0.058)
Beta Half-life (hr) | 1,240 (110) | 1,630 (170)
K_10_ (1/hr) | 0.0098 (0.0011) | 0.0086 (0.0010)
K_10_ Half-life (hr) | 70.5 (8) | 80.9 (9.7)
K_12_ | 0.876 (0.081) | 0.902 (0.075)
K_21_ | 0.0535 (0.0039) | 0.0476 (0.0031)
CL_1_ (mL/hr/kg) | 7.71 (0.54) | 5.74 (0.5)
CL_2_ (mL/hr/kg) | 687 (39) | 604 (31)
V_1_ (mL/kg) | 784 (69) | 669 (54)
V_2_ (mL/kg) | 12,900 (500) | 12,700 (500)
V_ss_ (mL/kg) | 13,600 (500) | 13,300 (500)
MRT (hr*ng/mL) | 1,770 (160) | 2,330 (250)
AUC (hr*ng/mL) | 13,000 (900) | 174,000 (15,000)
AUC/Dose^c^ (hr*ng/mL/ µg/kg) | 130 (9) | 174 (15)

^a^ Based on a two-compartment model with first order elimination.

^b^ Data are presented as mean (standard error).

cDose-adjusted area under the tissue concentration-time curve.

Following gavage administration of HCB, maximum concentration (C_max_) was reached within 3–4 hours for all doses and increased in a dose-proportional manner (Figure D-2, Table D-8). The blood elimination half-life (K_10_ half-life) was 559 hours (~23 days) at the 30 µg/kg dose administered but fell to 284–295 hours (11–12 days) at the higher doses. The volume of distribution to the second compartment (V_2_) was high (7,110–9,180 mL/kg), exceeding the estimated volume of aqueous body volume in rats (668 mL/kg). The clearance increased and AUC per unit dose (dose-adjusted AUC) decreased with increasing dose. Bioavailability, calculated using both IV doses, exceeded 100% for most doses and decreased with increasing dose (Table D-9).

Figure D-2

Blood Concentrations versus Time Profiles of Hexachlorobenzene after a Single Gavage Administration of a 30 (A), 300 (B), or 30,000 (C) µg/kg Dose in Female Rats

Two-compartmental model with first order input, first order output, and 1/y^2^ weighting was used to fit the data (shown as solid line).

Table D-8 Plasma Toxicokinetic Parameters of Hexachlorobenzene Following Single Gavage Administration in Female Rats^a^

Parameter^b^ | Dose
Parameter^b^ | 30 µg/kg | 300 µg/kg | 30,000 µg/kg
C_max_ (ng/mL) | 10.6 (1.1) | 67.5 (7.8) | 6,630 (750)
C_max_/Dose (ng/mL/µg/kg) | 0.35 (0.04) | 0.23 (0.03) | 0.22 (0.03)
T_max_ (hr) | 4.23 (0.38) | 4.11 (0.37) | 3.18 (0.34)
Alpha Half-life (hr) | 3.30 (3.21) | 2.86 (4.34) | 2.46 (1.93)
Beta Half-life (hr) | 3,340 (1060) | 1,560 (210) | 1,190 (120)
K_10_ (1/hr) | 0.00124 (0.0012) | 0.00235 (0.0033) | 0.00244 (0.0017)
K_10_ Half-life (hr) | 559 (526) | 295 (414) | 284 (202)
K_12_ | 0.174 (0.198) | 0.194 (0.357) | 0.212 (0.212)
K_21_ | 0.0351 (0.0068) | 0.0459 (0.0095) | 0.067 (0.0132)
CL_1__F (mL/hr/kg) | 1.78 (0.5) | 5.1 (0.55) | 6.06 (0.44)
CL_2__F (mL/hr/kg) | 250 (75) | 421 (195) | 527 (170)
V_1__F (mL/kg) | 1,440 (1,240) | 2,170 (3,020) | 2,480 (1,750)
V_2__F (mL/kg) | 7,110 (1,230) | 9,180 (2,930) | 7,860 (1,710)
AUC (hr*ng/mL) | 16,800 (4,700) | 58,800 (6,300) | 4,950,000 (360,000)
AUC/Dose^c^ (hr*ng/mL/µg/kg) | 560 (157) | 196 (21) | 165 (12)

^a^ Based on two-compartment model with first order absorption and elimination.

^b^ Data are presented as mean (standard error).

^c^ Dose-adjusted area under the tissue concentration-time curve.

Table D-9 Bioavailability of Hexachlorobenzene Following Single Gavage Administration in Female Rats

Gavage Dose | Bioavailability (%) Calculated Using 100 µg/kg IV Data | Bioavailability (%) Calculated Using 1,000 µg/kg IV Data
30 µg/kg | 430 | 321
300 µg/kg | 151 | 113
30,000 µg/kg | 127 | 95

IV = intravenous.

### D.3.3 Tissue Toxicokinetics of Hexachlorobenzene

Tissues were collected as early as 2 hours and up to 84 days postadministration (Table D-2). Concentrations of HCB in tissue over time are shown in Figure D-3 and Figure D-4. Kinetic parameters of HCB in tissues were estimated using NCA (Table D-10). Kinetic parameters in the tissues were similar across routes of administration; only data from gavage administration, the more relevant route of administration, will be discussed. Adipose had the highest C_max_ while lung had the lowest. In adipose tissue, the time to reach maximum concentration (T_max_) ranged from 24–72 hours and the increase in C_max_ was generally proportional to dose. The λ half-life of HCB in adipose ranged from 47–157 days. In the liver, the C_max_ was reached at 3 hours and increased proportionally with dose. The λ half-life of HCB in the liver was 41–85 days. In the lung, the T_max_ ranged from 2–8 hours. The C_max_ was generally dose-proportional and the λ half-life ranged from 32–122 days. For all tissues, the dose-adjusted AUC tended to decrease with increasing dose; this decrease was greatest in the adipose tissue. Adipose:blood AUC ratios were consistently high in all dose groups, ranging from 42.2 to 56.8 (Table D-11). In the liver and lung, the ratios were generally at or above 1 but did not exceed 4.

Figure D-3

Concentrations of Hexachlorobenzene Over Time in Adipose Tissue (A–B), Liver (C–D), and Lung (E–F) after a Single Intravenous Administration of a 100 or 1,000 µg/kg Dose in Female Rats

Noncompartmental analysis was used to evaluate these data.

Figure D-4

Concentrations of Hexachlorobenzene Over Time in Adipose Tissue (A–C), Liver (D–F), and Lung (G–I) after a Single Gavage Administration of a 30, 300, or 30,000 µg/kg Dose in Female Rats

Noncompartmental analysis (solid line) was used to evaluate these data.

Table D-10 Toxicokinetic Parameters of Hexachlorobenzene in Tissues Following Single Administration in Female Rats^a^

Tissue | Route of Administration | Dose (µg/kg) | C_max_ (ng/g) | C_max_/Dose (ng/mL/µg/kg) | T_max_ (hr) | λ Half-life (hr) | AUC (hr*ng/g) | AUC/Dose^b^ (hr*ng/g)/ µg/kg)
Adipose | IV | 100 | 334 | 3.34 | 336 | 1,230 | 608,000 | 6,080
Adipose | IV | 1,000 | 3,180 | 3.18 | 72 | 1,740 | 8,270,000 | 8,270
Adipose | Oral | 30 | 226 | 7.53 | 72 | 3,770 | 903,000 | 30,100
Adipose | Oral | 300 | 1,320 | 4.40 | 72 | 1,140 | 2,480,000 | 8,267
Adipose | Oral | 30,000 | 168,000 | 5.60 | 24 | 1,120 | 281,000,000 | 9,367
Liver | IV | 100 | 82.4 | 0.82 | 2 | 1,350 | 45,800 | 458
Liver | IV | 1,000 | 630 | 0.63 | 2 | 1,950 | 404,000 | 404
Liver | Oral | 30 | 39.6 | 1.32 | 3 | 2,050 | 28,800 | 960
Liver | Oral | 300 | 202 | 0.67 | 3 | 981 | 122,000 | 407
Liver | Oral | 30,000 | 16,100 | 0.54 | 3 | 1,470 | 9,550,000 | 318
Lung | IV | 100 | 101 | 1.01 | 2 | 860 | 19,700 | 197
Lung | IV | 1,000 | 2,180 | 2.18 | 2 | 1,280 | 287,000 | 287
Lung | Oral | 30 | 11 | 0.37 | 3 | 1,480 | 13,300 | 443
Lung | Oral | 300 | 127 | 0.42 | 3 | 763 | 82,200 | 274
Lung | Oral | 30,000 | 4,420 | 0.15 | 8 | 2,930 | 11,300,000 | 377

C_max_ = maximum concentration; T_max_ = time to maximum concentration; AUC = area under the curve; IV = intravenous.

^a^ Based on noncompartmental analysis.

^b^ Dose-normalized area under the tissue concentration-time curve.

Table D-11 Ratio of Tissue and Blood Mean Area under the Curve

Tissue | Route of Administration | Dose (µg/kg) | Ratio
Adipose | IV | 100 | 46.8
Adipose | IV | 1,000 | 47.5
Adipose | Oral | 30 | 53.8
Adipose | Oral | 300 | 42.2
Adipose | Oral | 30,000 | 56.8
Liver | IV | 100 | 3.5
Liver | IV | 1,000 | 2.3
Liver | Oral | 30 | 1.7
Liver | Oral | 300 | 2.1
Liver | Oral | 30,000 | 1.9
Lung | IV | 100 | 1.5
Lung | IV | 1,000 | 1.6
Lung | Oral | 30 | 0.8
Lung | Oral | 300 | 1.4
Lung | Oral | 30,000 | 2.3

IV = intravenous.

## D.4 Summary

Numerous studies in humans and in various animal models have yielded a great understanding of HCB absorption, distribution, metabolism, and elimination. However, estimates of half-life, particularly in female rats, have not been adequately reported. This study was designed to generate data to determine the toxicokinetic parameters of HCB in female Sprague Dawley rats to complement the toxic equivalency factor studies.

Overall, results from this study corroborate the existing literature about the absorption and distribution of HCB. Orally administered HCB was rapidly absorbed and distributed to the mesenteric adipose tissue, liver, and lung. Blood C_max_ increased proportionally with dose, though the AUC appeared to have nonlinear kinetics, as the dose-adjusted AUC was reduced at the two highest doses. Measurement of HCB and its metabolites in urine, feces, and tissues would help determine if the primary driver of these changes is metabolism or elimination. The half-lives observed in rats were shorter than estimated half-lives in humans. Bioavailability of HCB exceeded 100% at most doses. Given its lipophilicity, HCB administered IV may not be as efficiently absorbed by tissues and thus excreted faster, resulting in lower tissue accumulation and lower systemic exposure leading to bioavailability values exceeding 100%. Interestingly, bioavailability decreases at the higher oral doses of HCB suggesting some saturation of absorption or elimination processes.