# Appendix C Sentinel Animal Program

## C.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that could affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera from extra (sentinel) or exposed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

In the 3-month studies, blood samples were collected from each sentinel animal, allowed to clot, and the serum was separated. The serum samples were processed appropriately and sent to BioReliance Corporation (Rockville, MD) for determination of the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood was collected from 10 female rats during the quarantine period and at 4 weeks after the start of dosing; blood was collected from 9 female rats at study termination.

Table C-1 Methods and Results for Sentinel Animal Testing in Female Rats in the Three-month Study

Method and Test | Time of Collection
ELISA
Mycoplasma arthritidis | Study termination
Mycoplasma pulmonis | Study termination
Pneumonia Virus of Mice | End of quarantine; 4 weeks; study termination
Rat Coronavirus/Sialodacryoadenitis Virus | End of quarantine; 4 weeks; study termination
Sendai | End of quarantine; 4 weeks; study termination
Immunofluorescence Assay
Mycoplasma arthritidis | Study termination
Parvovirus | End of quarantine; 4 weeks; study termination

ELISA = enzyme-linked immunosorbent assay.

## C.2 Results

All test results were negative.