# Appendix B Ingredients, Nutrient Composition, and Contaminant Levels in NTP-2000 Rat Ration

Table B-1 Ingredients of NTP-2000 Rat Ration

Ingredients | Percent by Weight
Ground Hard Winter Wheat | 22.26
Ground #2 Yellow Shelled Corn | 22.18
Wheat Middlings | 15.0
Oat Hulls | 8.5
Alfalfa Meal (Dehydrated, 17% Protein) | 7.5
Purified Cellulose | 5.5
Soybean Meal (49% Protein) | 5.0
Fish Meal (60% Protein) | 4.0
Corn Oil (without Preservatives) | 3.0
Soy Oil (without Preservatives) | 3.0
Dried Brewer’s Yeast | 1.0
Calcium Carbonate (USP) | 0.9
Vitamin Premix^a^ | 0.5
Mineral Premix^b^ | 0.5
Calcium Phosphate, Dibasic (USP) | 0.4
Sodium Chloride | 0.3
Choline Chloride (70% Choline) | 0.26
Methionine | 0.2

USP = United States Pharmacopeia.

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table B-2 Vitamins and Minerals in NTP-2000 Rat Ration

| Amount^a^ | Source
Vitamins
Vitamin A | 4,000 IU | Stabilized vitamin A palmitate or acetate
Vitamin D | 1,000 IU | D-activated animal sterol
Vitamin K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl Acetate | 100 IU | –
Niacin | 23 mg | –
Folic Acid | 1.1 mg | –
d-Pantothenic Acid | 10 mg | d-Calcium pantothenate
Riboflavin | 3.3 mg | –
Thiamine | 4 mg | Thiamine mononitrate
Vitamin B_12_ | 52 µg | –
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | d-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

^a^ Per kg of finished product.

Table B-3 Nutrient Composition of NTP-2000 Rat Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by weight) | 14.2 ± 0.00 | 14.2–14.2 | 1
Crude Fat (% by weight) | 8.5 ± 0.00 | 8.5–8.5 | 1
Crude Fiber (% by weight) | 8.8 ± 0.00 | 8.8–8.8 | 1
Ash (% by weight) | 5.1 ± 0.00 | 5.1–5.1 | 1
Amino Acids (% of Total Diet)
Arginine | 0.783 ± 0.070 | 0.670–0.970 | 22
Cystine | 0.220 ± 0.024 | 0.150–0.250 | 22
Glycine | 0.701 ± 0.041 | 0.620–0.800 | 22
Histidine | 0.352 ± 0.077 | 0.270–0.680 | 22
Isoleucine | 0.546 ± 0.044 | 0.430–0.660 | 22
Leucine | 1.095 ± 0.067 | 0.960–1.240 | 22
Lysine | 0.711 ± 0.114 | 0.310–0.860 | 22
Methionine | 0.409 ± 0.046 | 0.260–0.490 | 22
Phenylalanine | 0.628 ± 0.040 | 0.540–0.720 | 22
Threonine | 0.505 ± 0.043 | 0.430–0.610 | 22
Tryptophan | 0.150 ± 0.028 | 0.110–0.200 | 22
Tyrosine | 0.401 ± 0.061 | 0.280–0.540 | 22
Valine | 0.665 ± 0.043 | 0.550–0.730 | 22
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.95 ± 0.259 | 3.49–4.55 | 22
Linolenic | 0.30 ± 0.032 | 0.21–0.35 | 22
Vitamins
Vitamin A (IU/kg) | 5,870 ± 0.00 | 5,870–5,870 | 1
Vitamin D (IU/kg) | 1,000^a^ | – | –
α-Tocopherol (ppm) | 80.6 ± 22.03 | 27.0–124.0 | 22
Thiamine (ppm)^b^ | 7.3 ± 0.00 | 7.3–7.3 | 1
Riboflavin (ppm) | 7.6 ± 2.89 | 4.20–17.50 | 22
Niacin (ppm) | 78.9 ± 9.08 | 66.4–98.2 | 22
Pantothenic Acid (ppm) | 26.9 ± 12.63 | 17.4–81.0 | 22
Pyridoxine (ppm)^b^ | 9.54 ± 1.99 | 6.44–13.7 | 22
Folic Acid (ppm) | 1.62 ± 0.48 | 1.15–3.27 | 22
Biotin (ppm) | 0.32 ± 0.10 | 0.20–0.704 | 22
Vitamin B_12_ (ppb) | 53.6 ± 39.6 | 18.3–174.0 | 22
Choline (as Chloride) (ppm) | 2,846 ± 485 | 1,820–3,790 | 22
Minerals
Calcium (%) | 1.140 ± 0.000 | 1.140–1.140 | 1
Phosphorus (%) | 0.632 ± 0.000 | 0.632–0.632 | 1
Potassium (%) | 0.666 ± 0.030 | 0.626–0.733 | 22
Chloride (%) | 0.386 ± 0.039 | 0.300–0.474 | 22
Sodium (%) | 0.189 ± 0.016 | 0.160–0.222 | 22
Magnesium (%) | 0.216 ± 0.062 | 0.185–0.490 | 22
Sulfur (%) | 0.170 ± 0.029 | 0.116–0.209 | 14
Iron (ppm) | 186 ± 39.2 | 135–311 | 22
Manganese (ppm) | 51.4 ± 10.28 | 21.0–73.1 | 22
Zinc (ppm) | 53.4 ± 8.46 | 43.3–78.5 | 22
Copper (ppm) | 7.01 ± 2.562 | 3.21–16.3 | 22
Iodine (ppm) | 0.503 ± 0.206 | 0.158–0.972 | 22
Chromium (ppm) | 0.694 ± 0.276 | 0.330–1.380 | 22
Cobalt (ppm) | 0.256 ± 0.164 | 0.098–0.864 | 22

^a^ From formulation.

^b^ As hydrochloride.

Table B-4 Contaminant Levels in NTP-2000 Rat Ration

| Mean ± Standard Deviation | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.17 ± 0.00 | 0.17–0.17 | 1
Cadmium (ppm) | 0.04 ± 0.00 | 0.04–0.04 | 1
Lead (ppm) | 0.07 ± 0.00 | 0.07–0.07 | 1
Mercury (ppm)^a^ | <0.02 | – | 1
Selenium (ppm) | 0.25 ± 0.00 | 0.25–0.25 | 1
Aflatoxins (ppb)^a^ | <5.00 | – | 1
Nitrate Nitrogen (ppm)^b^ | 6.85 ± 0.00 | 6.85–6.85 | 1
Nitrite Nitrogen (ppm)^a,b^ | <0.61 | – | 1
BHA (ppm)^a,c^ | <1.0 | – | 1
BHT (ppm)^a,c^ | <1.0 | – | 1
Aerobic Plate Count (CFU/gm) | 10 ± 0 | 10–10 | 1
Coliform (MPN/gm) | 3.6 ± 0 | 3.6–3.6 | 1
Escherichia coli (MPN/gm)^a^ | <10 | – | 1
Salmonella (MPN/gm) | Negative | – | 1
Total Nitrosamines (ppb)^d^ | 5.9 ± 0.00 | 5.9–5.9 | 1
N-Ndimethylamine (ppb)^d^ | 2.9 ± 0.00 | 2.9–2.9 | 1
N-Npyrrolidine (ppb)^d^ | 3.0 ± 0.00 | 3.0–3.0 | 1
Pesticides (ppm)
α-BHC^a^ | <0.01 | – | 1
β-BHC^a^ | <0.02 | – | 1
γ-BHC^a^ | <0.01 | – | 1
δ-BHC^a^ | <0.01 | – | 1
Heptachlor^a^ | <0.01 | – | 1
Aldrin^a^ | <0.01 | – | 1
Heptachlor Epoxide^a^ | <0.01 | – | 1
DDE^a^ | <0.01 | – | 1
DDD^a^ | <0.01 | – | 1
DDT^a^ | <0.01 | – | 1
HCB^a^ | <0.01 | – | 1
Mirex^a^ | <0.01 | – | 1
Methoxychlor^a^ | <0.05 | – | 1
Dieldrin^a^ | <0.01 | – | 1
Endrin^a^ | <0.01 | – | 1
Telodrin^a^ | <0.01 | – | 1
Chlordane^a^ | <0.05 | – | 1
Toxaphene^a^ | <0.10 | – | 1
Estimated PCBs^a^ | <0.20 | – | 1
Ronnel^a^ | <0.01 | – | 1
Ethion^a^ | <0.02 | – | 1
Trithion^a^ | <0.05 | – | 1
Diazinon^a^ | <0.10 | – | 1
Methyl Chlorpyrifos | 0.199 ± 0.00 | 0.199–0.199 | 1
Methyl Parathion^a^ | <0.02 | – | 1
Ethyl Parathion^a^ | <0.02 | – | 1
Malathion | 0.56 ± 0.00 | 0.557–0.557 | 1
Endosulfan I^a^ | <0.01 | – | 1
Endosulfan II^a^ | <0.01 | – | 1
Endosulfane Sulfate^a^ | <0.03 | – | 1

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.