# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization

### A.1.1 Hexachlorobenzene

Hexachlorobenzene (HCB) was obtained from Aldrich Chemical Company (Milwaukee, WI) in one lot (03915CU) that was used in the 3-month study. Identity and purity analyses were conducted by the analytical chemistry laboratory at Midwest Research Institute (MRIGlobal, Kansas City, MO); additional identity analyses were conducted by the study laboratory at Battelle (Columbus, OH). One additional lot (08526EF) was procured from Aldrich Chemical Company by the analytical chemistry laboratory solely for dose formulation stability studies and was not used in the 3-month animal study. Reports on analyses performed in support of the HCB study are on file at the National Institute of Environmental Health Sciences.

Lot 03915CU of the chemical, a white powder, was identified as HCB by the analytical chemistry laboratory using infrared (IR) spectroscopy and gas chromatography (GC) coupled with mass spectrometry (MS). The study laboratory confirmed the identity of the test article by IR spectroscopy. IR and MS spectra were consistent with the structure of HCB and comparable to literature spectra^170^ of HCB. Representative IR and MS spectra are presented in Figure A-1 and Figure A-2, respectively.

The purity of lot 03915CU was determined by GC with flame ionization detection (GC/FID) using System A (Table A-1). The purity assay indicated one major peak and one impurity with a peak area equal to 0.05% of the total peak area. The overall purity of lot 03915CU was determined to be >99%.

After the scheduled termination of the animals, bulk chemical reanalysis was performed by the study laboratory using GC/FID by System B, and no degradation of the bulk chemical was detected. To ensure stability, the bulk chemical was stored at room temperature in an amber glass bottle.

### A.1.2 Formulation Materials

United States Pharmacopeia (USP)-grade corn oil was obtained from Spectrum Quality Products (Gardena, CA) in two lots and was used with one lot of USP-grade acetone (Spectrum Quality Products) as the vehicle in the 3-month gavage study. The identity of the acetone was confirmed by the study laboratory using IR spectroscopy prior to its use. Purity of the acetone was determined to be ≥99.9% by the study laboratory using GC/FID by System C. The corn oil was analyzed twice by the study laboratory for peroxide levels by potentiometric titration; both measured values were below the 3 mEq/kg rejection criterion.

## A.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared by mixing stock solutions of HCB in acetone with corn oil or by mixing HCB with the vehicle (corn oil:acetone [99:1]) to achieve the required concentrations (Table A-2). The dose formulations were stored in amber glass bottles sealed with Teflon^®^-lined lids at room temperature for up to 34 days.

The study laboratory determined that a 10 mg/mL dose formulation in corn oil:acetone (99:1) was gavagable using a 20-gauge needle.

Homogeneity studies of the 0.012 and 10.0 mg/mL dose formulations in corn oil containing 1% acetone were performed by the study laboratory using GC with electron capture detection (ECD) by System D (Table A-1). Stability studies of a 1 μg/mL dose formulation made with lot 08526EF dissolved in 100% corn oil were performed by the analytical chemistry laboratory using a GC/ECD system similar to System D. Homogeneity was confirmed, and stability for at least 35 days was confirmed for dose formulations stored in sealed containers in the dark at 5°C and 25°C and for at least 3 hours under simulated animal room conditions.

Periodic analyses of the dose formulations of HCB were conducted by the study laboratory using GC/ECD by System D. During the 3-month study, the dose formulations were analyzed at the beginning, midpoint, and termination; all 21 dose formulations were within 10% of the target concentrations (Table A-3). Animal room samples of these dose formulations were also analyzed; 20 of 21 animal room samples were within 10% of the target concentrations.

Table A-1 Gas Chromatography Systems Used in the Three-month Gavage Study of Hexachlorobenzene^a^

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame ionization | DB-5, 30 m × 0.53 mm, 1.5-μm film thickness (Agilent Technologies Inc., Santa Clara, CA) | Helium at 10 mL/minute | 50°C for 5 minutes, then 10°C/minute to 250°C, held for 20 minutes
System B
Flame ionization | RTX^®^-5, 15 m × 0.53 mm, 1.0-μm film thickness (Restek Corporation, Bellafonte, PA) | Helium at ~10 mL/minute | Isothermal at 165°C
System C
Flame ionization | SUPELCOWAX^™^ 10, 30 m × 0.53 mm, 0.5-μm film thickness (Supelco, Inc., Bellefonte, PA) | Helium at ~10 mL/minute | 40°C for 5 minutes, then 10°C/minute to 220°C
System D
Electron capture | RTX^®^-5, 15 m × 0.53 mm, 1.0-μm film thickness (Restek Corporation) | Helium at ~10 mL/minute | 170°C for 9 minutes, then 30°C/minute to 250°C, held for 8 minutes

^a^ The gas chromatographs were manufactured by Hewlett-Packard (Palo Alto, CA).

Table A-2 Preparation and Storage of Dose Formulations in the Three-month Gavage Study of Hexachlorobenzene

Three-month Study
Preparation
To prepare the corn oil:acetone (99:1) vehicle, a specified amount of acetone was measured using a volumetric pipette and transferred into a calibrated glass mixing container approximately half-filled with corn oil. The contents of the container were diluted to volume with corn oil, and the container was capped, shaken vigorously, sonicated for approximately 90 minutes (allowing the temperature of the sonicator to reach approximately 40°C) with intermittent vigorous shaking, and shaken vigorously after sonication was complete. To prepare the 0.012 and 0.04 mg/mL dose formulations, stock solutions were made by weighing 60 and 200 mg of HCB, respectively, into individual 50 mL volumetric flasks, adding approximately 25 mL of acetone, capping the flask and shaking to mix, then diluting the contents to volume with acetone, capping, and shaking to mix. The flask was then vortexed for approximately 2 minutes, sonicated until the HCB was in solution, and inverted at least 10 times. Five mL of stock solution was measured with a volumetric pipette and transferred into a 500 mL glass mixing container approximately half-filled with corn oil. The container was capped and shaken vigorously, and the contents were diluted to final volume with corn oil. The container was recapped and then shaken and sonicated as described for the corn oil:acetone (99:1) vehicle. For the 0.12, 0.4, 1.2, 4, and 10 mg/mL dose formulations, the appropriate amount of HCB was weighed in a weigh boat and transferred into a 500 mL glass mixing container approximately half-filled with corn oil, while tapping the weigh boat to transfer as much of the test article as possible. Five mL of acetone was measured using a glass volumetric pipette and transferred into the container. The container was capped and shaken vigorously, and the contents were diluted to final volume with corn oil. The container was recapped and then shaken and sonicated as described for the corn oil:acetone (99:1) vehicle.
Chemical Lot Number
03915CU
Maximum Storage Time
34 days
Storage Conditions
Stored in amber glass bottles sealed with Teflon^®^-lined lids at room temperature.
Study Laboratory
Battelle (Columbus, OH)

Table A-3 Results of Analyses of Dose Formulations Administered to Female Rats in the Threemonth Gavage Study of Hexachlorobenzene

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
January 2–3, 2001 | January 4–8, 2001 | 0.012 | 0.01157 | −4
| | 0.04 | 0.03697 | −8
| | 0.12 | 0.1210 | +1
| | 0.4 | 0.4008 | 0
| | 1.2 | 1.197 | 0
| | 4 | 4.325 | +8
| | 10 | 10.64 | +6
| February 8–9, 2001^b^ | 0.012 | 0.01166 | −3
| | 0.04 | 0.03688 | −8
| | 0.12 | 0.1175 | −2
| | 0.4 | 0.3948 | −1
| | 1.2 | 1.180 | −2
| | 4 | 3.870 | −3
| | 10 | 9.844 | −2
February 26, 2001 | February 28–March 1, 2001 | 0.012 | 0.01138 | −5
| | 0.04 | 0.03860 | −4
| | 0.12 | 0.1239 | +3
| | 0.4 | 0.3946 | −1
| | 1.2 | 1.196 | 0
| | 4 | 3.960 | −1
| | 10 | 9.735 | −3
| April 3–4, 2001^b^ | 0.012 | 0.01157 | −4
| | 0.04 | 0.03793 | −5
| | 0.12 | 0.1173 | −2
| | 0.4 | 0.3888 | −3
| | 1.2 | 1.191 | −1
| | 4 | 3.946 | −1
| | 10 | 9.935 | −1
March 22, 2001 | March 27, 2001 | 0.012 | 0.01255 | +5
| | 0.04 | 0.03698 | −8
| | 0.12 | 0.1146 | −5
| | 0.4 | 0.3893 | −3
| | 1.2 | 1.164 | −3
| | 4 | 4.164 | +4
| | 10 | 9.494 | −5
| April 17–18, 2001^b^ | 0.012 | 0.01189 | −1
| | 0.04 | 0.03959 | −1
| | 0.12 | 0.1059 | −12
| | 0.4 | 0.4033 | +1
| | 1.2 | 1.256 | +5
| | 4 | 4.060 | +2
| | 10 | 10.36 ± 0.03^c^ | +4

^a^ Results of duplicate analyses. Dosing volume = 2.5 mL/kg; 0.012 mg/mL = 0.03 mg/kg, 0.04 mg/mL = 0.1 mg/kg, 0.12 mg/mL = 0.3 mg/kg, 0.4 mg/mL = 1 mg/kg, 1.2 mg/mL = 3 mg/kg, 4 mg/mL = 10 mg/kg, 10 mg/mL = 25 mg/kg.

^b^ Animal room samples.

^c^ Results of triplicate analyses (mean ± standard deviation).

Figure A-1

Infrared Absorption Spectrum of Hexachlorobenzene

Figure A-2

Mass Spectrum of Hexachlorobenzene