# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8992

DOI: https://doi.org/10.22427/NTP-TOX-107

Report Series: NTP Toxicity Report Series

Report Series Number: 107

Official citation: National Toxicology Program (NTP). 2024. NTP technical report on the toxicity study of Stachybotrys chartarum (CASRN 67892-26-6) administered by inhalation to B6C3F1/N mice. Research Triangle Park, NC: National Toxicology Program. Toxicity Report 107.