# Peer Review

The National Toxicology Program (NTP) conducted a peer review of the draft NTP Technical Report on the Toxicity Study of Stachybotrys chartarum (CASRN 67892-26-6) Administered by Inhalation to B6C3F1/N Mice by letter in January 2024 by the experts listed below. Reviewer selection and document review followed established NTP practices. The reviewers were charged to:

1. Peer review the draft NTP Technical Report on the Toxicity Study of Stachybotrys chartarum (CASRN 67892-26-6) Administered by Inhalation to B6C3F1/N Mice.
2. Comment on NTP’s interpretations of the data.

NTP carefully considered reviewer comments in finalizing this report.

## Peer Reviewers

- Kara Corps, D.V.M., Ph.D.
  Assistant Professor, College of Veterinary Medicine
  The Ohio State University
  Columbus, Ohio, USA
- James Pestka, Ph.D.
  University Distinguished Professor, Department of Food Science and Human Nutrition, Department of Microbiology and Molecular Genetics, Institute for Integrative Toxicology
  Michigan State University
  East Lansing, Michigan, USA