# Collaborators

- Division of Translational Toxicology, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Designed study, evaluated and interpreted results, and reported findings
  D.R. Germolec, Ph.D., Lead Scientist
  C.R. Blystone, Ph.D.
  M.F. Cesta, D.V.M., Ph.D.
  B.J. Collins, M.S.P.H.
  M.C. Cora, D.V.M.
  H.C. Cunny, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  D.E. Malarkey, D.V.M., Ph.D. (Retired)
  G.K. Roberts, Ph.D.
  K.A. Shipkowski, Ph.D.
  K.R. Shockley, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G. Travlos, Ph.D.
  N.J. Walker, Ph.D.
- Provided oversight for data management
  J.M. Fostel, Ph.D.
- Integrated Laboratory Systems, LLC, an Inotiv Company, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  C.J. Willson, D.V.M., Ph.D., Lead Pathologist
- Coordinated pathology data review and coordinated Pathology Working Group (3-month study) (October 25, 2022)
  R.R. Moore, D.V.M.
- National Institute for Occupational Safety and Health, Morgantown, West Virginia, USA
  Developed test article and exposure system, conducted study, evaluated and interpreted results, and reported findings
  D.H. Beezhold, Ph.D., Co-Principal Investigator (Retired)
  T.L. Croston, Ph.D., Co-Principal Investigator
  B.J. Green, Ph.D., Co-Principal Investigator
  L. Battelli, M.S.
  W.T. Goldsmith, B.S.
  B.F. Law, M.S.
  A.R. Lemons, M.S.
  W.G. McKinney, M.S.
  A.P. Nayak, Ph.D.
  M.S. Orandle, D.V.M., Ph.D.
- Battelle, Columbus, Ohio, USA
  Evaluated pathology findings
  K.A.B. Knostman, D.V.M., Ph.D.
  K.M. Patton, D.V.M., Ph.D.
- ICF, Reston, Virginia, USA
  Contributed to technical writing and data integration and ensured report quality
  S.A. Gillera, Ph.D.
  L.M. Prince, Ph.D.