# References

1 Andersen B, Nielsen KF, Jarvis BB. Characterization of Stachybotrys from water-damaged buildings based on morphology, growth, and metabolite production. Mycologia. 2002; 94(3):392–403. 10.1080/15572536.2003.11833204 21156510
2 Kung’u J. Is black mold (Stachybotrys) a new emerging opportunistic human fungal pathogen? Mississauga, Ontario, Canada: Mold & Bacteria Consulting Laboratories; 2020. https://www.moldbacteria.com/mold/is-black-mold-stachybotrys-a-new-emerging-opportunistic-human-fungal-pathogen.html.
3 Blackwell M. The fungi: 1, 2, 3 … 5.1 million species? Am J Bot. 2011; 98(3):426–438. 10.3732/ajb.1000298 21613136
4 Green BJ. Occupational fungal exposure in the United States. In: Viegas C, Viegas S, Gomes A, Täubel M, Sabino R, editors. Exposure to Microbiological Agents in Indoor and Occupational Environments. Cham, Switzerland: Springer; 2017. p. 3–33. 10.1007/978-3-319-61688-9_1
5 Gow NAR, Latge JP, Munro CA. The fungal cell wall: Structure, biosynthesis, and function. Microbiol Spectr. 2017; 5(3). 10.1128/microbiolspec.FUNK-0035-2016 28513415
6 Eduard W. Fungal spores: A critical review of the toxicological and epidemiological evidence as a basis for occupational exposure limit setting. Crit Rev Toxicol. 2009; 39(10):799–864. 10.3109/10408440903307333 19863384
7 Green BJ, Sercombe JK, Tovey ER. Fungal fragments and undocumented conidia function as new aeroallergen sources. J Allergy Clin Immunol. 2005; 115(5):1043–1048. 10.1016/j.jaci.2005.02.009 15867864
8 Cho SH, Seo SC, Schmechel D, Grinshpun SA, Reponen T. Aerodynamic characteristics and respiratory deposition of fungal fragments. Atmos Environ. 2005; 39(30):5454–5465. 10.1016/j.atmosenv.2005.05.042
9 Green BJ, Schmechel D, Summerbell RC. Aerosolized fungal fragments. In: Adan OCG, Samson RA, editors. Fundamentals of Mold Growth in Indoor Environments and Strategies for Healthy Living. Wageningen, Netherlands: Wageningen Academic Publishers; 2011. p. 211–243. 10.3920/9789086867226_009
10 Adhikari A, Reponen T, Rylander R. Airborne fungal cell fragments in homes in relation to total fungal biomass. Indoor Air. 2013; 23(2):142–147. 10.1111/j.1600-0668.2012.00799.x 22804753
11 Reponen T, Seo SC, Grimsley F, Lee T, Crawford C, Grinshpun SA. Fungal fragments in moldy houses: A field study in homes in New Orleans and southern Ohio. Atmos Environ (1994). 2007; 41(37):8140–8149. 10.1016/j.atmosenv.2007.06.027 19050738
12 Afanou KA, Straumfors A, Skogstad A, Nilsen T, Synnes O, Skaar I, Hjeljord L, Tronsmo A, Green BJ, Eduard W. Submicronic fungal bioaerosols: High-resolution microscopic characterization and quantification. Appl Environ Microbiol. 2014; 80(22):7122–7130. 10.1128/AEM.01740-14 25217010
13 Gravesen S, Nielsen PA, Iversen R, Nielsen KF. Microfungal contamination of damp buildingss—examples of risk constructions and risk materials. Environ Health Perspect. 1999; 107 Suppl 3:505–508. 10.1289/ehp.99107s3505 10347000
14 Centers for Disease Control and Prevention (CDC). Acute pulmonary hemorrhage/hemosiderosis among infants — Cleveland, January 1993–November 1994. MMWR Morb Mortal Wkly Rep. 1994; 43(48):881–883. 7969010
15 Centers for Disease Control and Prevention (CDC). Update: Pulmonary hemorrhage/hemosiderosis among infants — Cleveland, Ohio, 1993–1996. MMWR Morb Mortal Wkly Rep. 1997; 46(2):33–35. 9011781
16 Institute of Medicine (IOM). Damp indoor spaces and health. Washington, DC: The National Academies Press; 2004. https://nap.nationalacademies.org/catalog/11011/damp-indoor-spaces-and-health
17 World Health Organization (WHO). WHO guidelines for indoor air quality: Dampness and mould. Geneva, Switzerland: World Health Organization, Regional Ofﬁce for Europe; 2009. https://www.who.int/publications/i/item/9789289041683
18 Mendell MJ, Mirer AG, Cheung K, Tong M, Douwes J. Respiratory and allergic health effects of dampness, mold, and dampness-related agents: A review of the epidemiologic evidence. Environ Health Perspect. 2011; 119(6):748–756. 10.1289/ehp.1002410 21269928
19 Baxi SN, Portnoy JM, Larenas-Linnemann D, Phipatanakul W, Environmental Allergens Workgroup. Exposure and health effects of fungi on humans. J Allergy Clin Immunol Pract. 2016; 4(3):396–404. 10.1016/j.jaip.2016.01.008 26947460
20 Benedict K, Jackson BR, Chiller T, Beer KD. Estimation of direct healthcare costs of fungal diseases in the United States. Clin Infect Dis. 2019; 68(11):1791–1797. 10.1093/cid/ciy776 30204844
21 Nikulin M, Reijula K, Jarvis BB, Hintikka EL. Experimental lung mycotoxicosis in mice induced by Stachybotrys atra. Int J Exp Pathol. 1996; 77(5):213–218. 10.1046/j.1365-2613.1996.9250323.x 8977373
22 Rao CY, Brain JD, Burge HA. Reduction of pulmonary toxicity of Stachybotrys chartarum spores by methanol extraction of mycotoxins. Appl Environ Microbiol. 2000; 66(7):2817–2821. 10.1128/AEM.66.7.2817-2821.2000 10877773
23 Rand TG, Mahoney M, White K, Oulton M. Microanatomical changes in alveolar type II cells in juvenile mice intratracheally exposed to Stachybotrys chartarum spores and toxin. Toxicol Sci. 2002; 65(2):239–245. 10.1093/toxsci/65.2.239 11812928
24 Yike I, Rand TG, Dearborn DG. Acute inflammatory responses to Stachybotrys chartarum in the lungs of infant rats: Time course and possible mechanisms. Toxicol Sci. 2005; 84(2):408–417. 10.1093/toxsci/kfi080 15647601
25 Ochiai E, Kamei K, Watanabe A, Nagayoshi M, Tada Y, Nagaoka T, Sato K, Sato A, Shibuya K. Inhalation of Stachybotrys chartarum causes pulmonary arterial hypertension in mice. Int J Exp Pathol. 2008; 89(3):201–208. 10.1111/j.1365-2613.2008.00585.x 18460072
26 Korpi A, Kasanen JP, Raunio P, Kosma VM, Virtanen T, Pasanen AL. Effects of aerosols from nontoxic Stachybotrys chartarum on murine airways. Inhal Toxicol. 2002; 14(5):521–540. 10.1080/089583701753678607 12028806
27 Croston TL, Lemons AR, Barnes MA, Goldsmith WT, Orandle MS, Nayak AP, Germolec DR, Green BJ, Beezhold DH. Inhalation of Stachybotrys chartarum fragments induces pulmonary arterial remodeling. Am J Respir Cell Mol Biol. 2020; 62(5):563–576. 10.1165/rcmb.2019-0221OC 31671270
28 Lemons AR, Croston TL, Goldsmith WT, Barnes MA, Jaderson MA, Park JH, McKinney W, Beezhold DH, Green BJ. Cultivation and aerosolization of Stachybotrys chartarum for modeling pulmonary inhalation exposure. Inhal Toxicol. 2019; 31(13-14):446–456. 10.1080/08958378.2019.1705939 31874574
29 Nayak AP, Croston TL, Lemons AR, Goldsmith WT, Marshall NB, Kashon ML, Germolec DR, Beezhold DH, Green BJ. Aspergillus fumigatus viability drives allergic responses to inhaled conidia. Ann Allergy Asthma Immunol. 2018; 121(2):200–210.e2. 10.1016/j.anai.2018.04.008 29660515
30 National Toxicology Program (NTP). NTP technical report on the toxicity studies of Aspergillus fumigatus administered by inhalation to B6C3F1/N mice (revised). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2021. NTP Toxicity Report 100. 10.22427/NTP-TOX-100
31 Kirk PM, Cannon PF, Minter DW, Stalpers JA. Dictionary of the fungi. 10th ed. Wallingford, UK: CABI International; 2008.
32 Ehrenberg CG. Sylvae mycologicae Berolinensis [dissertation]. University of Berlin; 1818. https://www.google.com/books/edition/_/gO5hAAAAcAAJ?gbpv=1
33 Corda ACJ. Icones fungorum hucusque cognitorum. Auctore A. C. J. Corda. Pragæ, 1837. Ann Mag Nat Hist Ser 1. 1838; 2(7):61–63. 10.1080/00222933809496655
34 Izabel TdSS, da Cruz ACR, Barbosa FR, Ferreira SML, Marques MFO, Gusmão LFP. The genus Stachybotrys (anamorphic fungi) in the semi-arid region of Brazil. Rev Bras Bot. 2010; 33(3):479–487. 10.1590/S0100-84042010000300010
35 Andersson MA, Nikulin M, Köljalg U, Andersson MC, Rainey F, Reijula K, Hintikka EL, Salkinoja-Salonen M. Bacteria, molds, and toxins in water-damaged building materials. Appl Environ Microbiol. 1997; 63(2):387–393. 10.1128/aem.63.2.387-393.1997 9023919
36 Boutin-Forzano S, Charpin-Kadouch C, Chabbi S, Bennedjai N, Dumon H, Charpin D. Wall relative humidity: A simple and reliable index for predicting Stachybotrys chartarum infestation in dwellings. Indoor Air. 2004; 14(3):196–199. 10.1111/j.1600-0668.2004.00233.x 15104787
37 Pestka JJ, Yike I, Dearborn DG, Ward MDW, Harkema JR. Stachybotrys chartarum, trichothecene mycotoxins, and damp building-related illness: New insights into a public health enigma. Toxicol Sci. 2008; 104(1):4–26. 10.1093/toxsci/kfm284 18007011
38 Grant C, Hunter CA, Flannigan B, Bravery AF. The moisture requirements of moulds isolated from domestic dwellings. Int Biodeterior. 1989; 25(4):259–284. 10.1016/0265-3036(89)90002-X
39 Frazer S, Magan N, Aldred D. The influence of water activity and temperature on germination, growth and sporulation of Stachybotrys chartarum strains. Mycopathologia. 2011; 172(1):17–23. 10.1007/s11046-011-9394-x 21347692
40 Mahmoudi M, Gershwin ME. Sick building syndrome. III. Stachybotrys chartarum. J Asthma. 2000; 37(2):191–198. 10.3109/02770900009055442 10805208
41 Kuhn DM, Ghannoum MA. Indoor mold, toxigenic fungi, and Stachybotrys chartarum: Infectious disease perspective. Clin Microbiol Rev. 2003; 16(1):144–172. 10.1128/CMR.16.1.144-172.2003 12525430
42 Madsen AM, Larsen ST, Koponen IK, Kling KI, Barooni A, Karottki DG, Tendal K, Wolkoff P. Generation and characterization of indoor fungal aerosols for inhalation studies. Appl Environ Microbiol. 2016; 82(8):2479–2493. 10.1128/AEM.04063-15 26921421
43 Miller JD, Rand TG, Jarvis BB. Stachybotrys chartarum: Cause of human disease or media darling? Med Mycol. 2003; 41(4):271–291. 10.1080/1369378031000137350 12964721
44 Hossain MA, Ahmed MS, Ghannoum MA. Attributes of Stachybotrys chartarum and its association with human disease. J Allergy Clin Immunol. 2004; 113(2):200–208. 10.1016/j.jaci.2003.12.018 14767429
45 Hodgson M, Dearborn DG. Human pulmonary disease and exposure to Stachybotrys chartarum and other toxigenic fungi. J Occup Environ Med. 2002; 44(8):705–707. 10.1097/00043764-200208000-00004 12185790
46 Jarvis BB, Sorenson WG, Hintikka EL, Nikulin M, Zhou Y, Jiang J, Wang S, Hinkley S, Etzel RA, Dearborn D. Study of toxin production by isolates of Stachybotrys chartarum and Memnoniella echinata isolated during a study of pulmonary hemosiderosis in infants. Appl Environ Microbiol. 1998; 64(10):3620–3625. 10.1128/AEM.64.10.3620-3625.1998 9758776
47 Brasel TL, Martin JM, Carriker CG, Wilson SC, Straus DC. Detection of airborne Stachybotrys chartarum macrocyclic trichothecene mycotoxins in the indoor environment. Appl Environ Microbiol. 2005; 71(11):7376–7388. 10.1128/AEM.71.11.7376-7388.2005 16269780
48 Fog Nielsen K. Mycotoxin production by indoor molds. Fungal Genet Biol. 2003; 39(2):103–117. 10.1016/S1087-1845(03)00026-4 12781669
49 Andersen B, Nielsen KF, Thrane U, Szaro T, Taylor JW, Jarvis BB. Molecular and phenotypic descriptions of Stachybotrys chlorohalonata sp. nov. and two chemotypes of Stachybotrys chartarum found in water-damaged buildings. Mycologia. 2003; 95(6):1227–1238. 10.1080/15572536.2004.11833031 21149024
50 Jarvis BB, Lee YW, Cömezoglu SN, Yatawara CS. Trichothecenes produced by Stachybotrys atra from eastern Europe. Appl Environ Microbiol. 1986; 51(5):915–918. 10.1128/aem.51.5.915-918.1986 3729393
51 Gao P, Martin J. Volatile metabolites produced by three strains of Stachybotrys chartarum cultivated on rice and gypsum board. Appl Occup Environ Hyg. 2002; 17(6):430–436. 10.1080/10473220290035462 12049433
52 Forgacs J. Stachybotryotoxicosis. In: Kadis S, Ciegler A, Ajl SJ, editors. Microbial Toxins: A Comprehensive Treatise, Volume VIII: Fungal Toxins. New York, NY: Academic Press; 1972. p. 95–128.
53 Drobotko VG. Stachybotryotoxicosis: A new disease of horses and humans. Am Rev Sov Med. 1945; 2(3):238–242.
54 Akkmeteli MA. Epidemiological features of the mycotoxicoses. Ann Nutr Aliment. 1977; 31(4-6):957–975. 77650
55 Croft WA, Jarvis BB, Yatawara CS. Airborne outbreak of trichothecene toxicosis. Atmos Environ. 1986; 20(3):549–552. 10.1016/0004-6981(86)90096-X
56 Hodgson MJ, Morey P, Leung WY, Morrow L, Miller D, Jarvis BB, Robbins H, Halsey JF, Storey E. Building-associated pulmonary disease from exposure to Stachybotrys chartarum and Aspergillus versicolor. J Occup Environ Med. 1998; 40(3):241–249. 10.1097/00043764-199803000-00006 9531095
57 Johanning E. Health problems related to fungal exposure: The example of toxigenic Stachybotrys chartarum (atra). In: Johanning E, Yang CS, editors. Fungi and Bacteria in Indoor Air Environments: Health Effects, Detection, and Remediation: Proceedings of the International Conference, Saratoga Springs, New York, October 6-7, 1994. Latham, NY: Eastern New York Occupational Health Program; 1995. p. 201-208.
58 Johanning E, Biagini R, Hull D, Morey P, Jarvis B, Landsbergis P. Health and immunology study following exposure to toxigenic fungi (Stachybotrys chartarum) in a water-damaged office environment. Int Arch Occup Environ Health. 1996; 68(4):207–218. 10.1007/s004200050052 8738349
59 Cooley JD, Wong WC, Jumper CA, Straus DC. Correlation between the prevalence of certain fungi and sick building syndrome. Occup Environ Med. 1998; 55(9):579–584. 10.1136/oem.55.9.579 9861178
60 Etzel R, Rylander R. Indoor mold and children’s health. Environ Health Perspect. 1999; 107 Suppl 3:463. 10.1289/ehp.107-1566224 10346994
61 Tuomi T, Reijula K, Johnsson T, Hemminki K, Hintikka EL, Lindroos O, Kalso S, Koukila-Kähkölä P, Mussalo-Rauhamaa H, Haahtela T. Mycotoxins in crude building materials from water-damaged buildings. Appl Environ Microbiol. 2000; 66(5):1899–1904. 10.1128/AEM.66.5.1899-1904.2000 10788357
62 Li DW, Yang CS. Fungal contamination as a major contributor to sick building syndrome. Adv Appl Microbiol. 2004; 55:31–112. 10.1016/S0065-2164(04)55002-5 15350790
63 Hintikka EL. The role of stachybotrys in the phenomenon known as sick building syndrome. Adv Appl Microbiol. 2004; 55:155–173. 10.1016/S0065-2164(04)55005-0 15350793
64 Dearborn DG, Yike I, Sorenson WG, Miller MJ, Etzel RA. Overview of investigations into pulmonary hemorrhage among infants in Cleveland, Ohio. Environ Health Perspect. 1999; 107 Suppl 3:495–499. 10.1289/ehp.99107s3495 10346998
65 Dearborn DG, Smith PG, Dahms BB, Allan TM, Sorenson WG, Montana E, Etzel RA. Clinical profile of 30 infants with acute pulmonary hemorrhage in Cleveland. Pediatrics. 2002; 110(3):627–637. 10.1542/peds.110.3.627 12205270
66 Fung F, Clark R, Williams S. Stachybotrys, a mycotoxin-producing fungus of increasing toxicologic importance. J Toxicol Clin Toxicol. 1998; 36(1-2):79–86. 10.3109/15563659809162592 9541050
67 Johanning E, Morey PR, Jarvis BB. Clinical-epidemiological investigation of health effects caused by Stachybotrys atra building contamination. In: Jaakkola JJK, Ilmarinen R, Seppanen O, editors. Indoor Air '93: Proceedings of the 6th International Conference on Indoor Air Quality and Climate, Volume 1: Health effects. Helsinki, Finland: Indoor Air '93; 1993. p. 225-230.
68 Etzel RA, Montaña E, Sorenson WG, Kullman GJ, Allan TM, Dearborn DG. Acute pulmonary hemorrhage in infants associated with exposure to Stachybotrys atra and other fungi. Arch Pediatr Adolesc Med. 1998; 152(8):757–762. 10.1001/archpedi.152.8.757 9701134
69 Kozak PP Jr, Gallup J, Cummins LH, Gillman SA. Currently available methods for home mold surveys. II. Examples of problem homes surveyed. Ann Allergy. 1980; 45(3):167–176. 6998332
70 Ochiai E, Kamei K, Hiroshima K, Watanabe A, Hashimoto Y, Sato A, Ando A. The pathogenicity of Stachybotrys chartarum. Nihon Ishinkin Gakkai Zasshi. 2005; 46(2):109–117. 10.3314/jjmm.46.109 15864257
71 Semis M, Dadwal SS, Tegtmeier BR, Wilczynski SP, Ito JI, Kalkum M. First case of invasive Stachybotrys sinusitis. Clin Infect Dis. 2021; 72(8):1386–1391. 10.1093/cid/ciaa231 32155243
72 Nelson BD. APSnet feature articles: Stachybotrys chartarum: The toxic indoor mold. St Paul, MN: American Phytopathological Society; 2001. https://www.apsnet.org/edcenter/apsnetfeatures/Pages/Stachybotrys.aspx.
73 Andrássy K, Horváth I, Lakos T, Töke Z. [Mass incidence of mycotoxicoses in Hajdu-Bihar County]. Mykosen. 1980; 23(3):130–133. 10.1111/j.1439-0507.1980.tb02593.x 7191050
74 El-Maghraby OMO, Bean GA, Jarvis BB, Aboul-Nasr MB. Macrocyclic trichothecenes produced by Stachybotrys isolated from Egypt and eastern Europe. Mycopathologia. 1991; 113(2):109–115. 10.1007/BF00442419 2034259
75 Gregory L, Pestka JJ, Dearborn DG, Rand TG. Localization of satratoxin-G in Stachybotrys chartarum spores and spore-impacted mouse lung using immunocytochemistry. Toxicol Pathol. 2004; 32(1):26–34. 10.1080/01926230490260790 14713545
76 Brasel TL, Douglas DR, Wilson SC, Straus DC. Detection of airborne Stachybotrys chartarum macrocyclic trichothecene mycotoxins on particulates smaller than conidia. Appl Environ Microbiol. 2005; 71(1):114–122. 10.1128/AEM.71.1.114-122.2005 15640178
77 Górny RL, Reponen T, Willeke K, Schmechel D, Robine E, Boissier M, Grinshpun SA. Fungal fragments as indoor air biocontaminants. Appl Environ Microbiol. 2002; 68(7):3522–3531. 10.1128/AEM.68.7.3522-3531.2002 12089037
78 Aleksic B, Draghi M, Ritoux S, Bailly S, Lacroix M, Oswald IP, Bailly JD, Robine E. Aerosolization of mycotoxins after growth of toxinogenic fungi on wallpaper. Appl Environ Microbiol. 2017; 83(16):e01001-17. 10.1128/AEM.01001-17 28646113
79 Jarvis BB. Macrocyclic trichothecenes. In: Sharma RP, Salunkhe DK, editors. Mycotoxins and Phytoalexins. Boca Raton, FL: CRC Press; 1991. p. 361–421.
80 Sorenson WG, Frazer DG, Jarvis BB, Simpson J, Robinson VA. Trichothecene mycotoxins in aerosolized conidia of Stachybotrys atra. Appl Environ Microbiol. 1987; 53(6):1370–1375. 10.1128/aem.53.6.1370-1375.1987 3496850
81 Yang GH, Jarvis BB, Chung YJ, Pestka JJ. Apoptosis induction by the satratoxins and other trichothecene mycotoxins: Relationship to ERK, p38 MAPK, and SAPK/JNK activation. Toxicol Appl Pharmacol. 2000; 164(2):149–160. 10.1006/taap.1999.8888 10764628
82 Islam Z, Harkema JR, Pestka JJ. Satratoxin G from the black mold Stachybotrys chartarum evokes olfactory sensory neuron loss and inflammation in the murine nose and brain. Environ Health Perspect. 2006; 114(7):1099–1107. 10.1289/ehp.8854 16835065
83 Mason CD, Rand TG, Oulton M, MacDonald JM, Scott JE. Effects of Stachybotrys chartarum (atra) conidia and isolated toxin on lung surfactant production and homeostasis. Nat Toxins. 1998; 6(1):27–33. 10.1002/(SICI)1522-7189(199802)6:1<27::AID-NT6>3.0.CO;2-B 9851509
84 Kankkunen P, Rintahaka J, Aalto A, Leino M, Majuri ML, Alenius H, Wolff H, Matikainen S. Trichothecene mycotoxins activate inflammatory response in human macrophages. J Immunol. 2009; 182(10):6418–6425. 10.4049/jimmunol.0803309 19414795
85 Vesper SJ, Dearborn DG, Yike I, Sorenson WG, Haugland RA. Hemolysis, toxicity, and randomly amplified polymorphic DNA analysis of Stachybotrys chartarum strains. Appl Environ Microbiol. 1999; 65(7):3175–3181. 10.1128/AEM.65.7.3175-3181.1999 10388719
86 Vesper S, Dearborn DG, Yike I, Allan T, Sobolewski J, Hinkley SF, Jarvis BB, Haugland RA. Evaluation of Stachybotrys chartarum in the house of an infant with pulmonary hemorrhage: Quantitative assessment before, during, and after remediation. J Urban Health. 2000; 77(1):68–85. 10.1007/BF02350963 10741843
87 Vesper SJ, Magnuson ML, Dearborn DG, Yike I, Haugland RA. Initial characterization of the hemolysin stachylysin from Stachybotrys chartarum. Infect Immun. 2001; 69(2):912–916. 10.1128/IAI.69.2.912-916.2001 11159985
88 Vesper SJ, Vesper MJ. Stachylysin may be a cause of hemorrhaging in humans exposed to Stachybotrys chartarum. Infect Immun. 2002; 70(4):2065–2069. 10.1128/IAI.70.4.2065-2069.2002 11895972
89 Elidemir O, Colasurdo GN, Rossmann SN, Fan LL. Isolation of Stachybotrys from the lung of a child with pulmonary hemosiderosis. Pediatrics. 1999; 104(4 Pt 1):964–966. 10.1542/peds.104.4.964 10506242
90 Rand TG, Flemming J, Miller JD, Womiloju TO. Comparison of inflammatory responses in mouse lungs exposed to atranones A and C from Stachybotrys chartarum. J Toxicol Environ Health A. 2006; 69(13):1239–1251. 10.1080/15287390500360307 16754538
91 Fung F, Hughson WG. Health effects of indoor fungal bioaerosol exposure. Appl Occup Environ Hyg. 2003; 18(7):535–544. 10.1080/10473220301451 12791550
92 Hardin BD, Kelman BJ, Saxon A. Adverse human health effects associated with molds in the indoor environment. J Occup Environ Med. 2003; 45(5):470–478. 10.1097/00043764-200305000-00006 12762072
93 Jagels A, Lindemann V, Ulrich S, Gottschalk C, Cramer B, Hübner F, Gareis M, Humpf HU. Exploring secondary metabolite profiles of Stachybotrys spp. by LC-MS/MS. Toxins (Basel). 2019; 11(3):133. 10.3390/toxins11030133 30818881
94 Korpinen EL. Studies on Stachybotrys alternans: IV. Effect of low doses of stachbotrys toxins on pregnancy of mice. Acta Pathol Microbiol Scand B Microbiol Immunol. 1974; 82(4):457–464. 4528746
95 Weyel DA, Ellakkani M, Alarie Y, Karol M. An aerosol generator for the resuspension of cotton dust. Toxicol Appl Pharmacol. 1984; 76(3):544–547. 10.1016/0041-008X(84)90359-4 6506079
96 Frazer DG, Robinson V, DeLong DS, Rose D, Tucker J, Weber KC, Olenchock SA, Jayaraman K. A system for exposing laboratory animals to cotton dust aerosol that is stabilized with feedback control. In: Jacobs RR, Waklyn PJ, editors. Proceedings of the Eleventh Cotton Dust Research Conference, Beltwide Cotton Research Conferences, Dallas, Texas, January 7-8, 1987. Memphis, TN: National Cotton Council; 1987. p. 74-78.
97 Frazer DG, Jones WG, Petsonk EL, Kullman GJ, Barger MW, Afshari A, Jones T, Castranova V. Organic dust exposure from compost handling: Response of an animal model. Am J Ind Med. 1993; 24(4):375–385. 10.1002/ajim.4700240404 8250058
98 Frazer DG, Robinson VA, Olenchock SA, Hahon N, Barger M, Castranova V. Comparison of the guinea pig's physiological and cellular response to the respirable fraction of untreated, heat treated, microwave irradiated and ethylene oxide treated DB 1/88 bulk cotton dust. In: Jacobs RR, Wakelyn PJ, Domelsmith LN, editors. Proceedings of the Fifteenth Cotton Dust Research Conference, Beltwide Cotton Conferences, San Antonio, Texas, January 11-12, 1991. Memphis, TN: National Cotton Council; 1991. p. 246-251.
99 McKinney W, Chen B, Frazer D. Computer controlled multi-walled carbon nanotube inhalation exposure system. Inhal Toxicol. 2009; 21(12):1053–1061. 10.1080/08958370802712713 19555230
100 Buskirk AD, Green BJ, Lemons AR, Nayak AP, Goldsmith WT, Kashon ML, Anderson SE, Hettick JM, Templeton SP, Germolec DR, et al. A murine inhalation model to characterize pulmonary exposure to dry Aspergillus fumigatus conidia. PLoS One. 2014; 9(10):e109855. 10.1371/journal.pone.0109855 25340353
101 Croston TL, Nayak AP, Lemons AR, Goldsmith WT, Gu JK, Germolec DR, Beezhold DH, Green BJ. Influence of Aspergillus fumigatus conidia viability on murine pulmonary microRNA and mRNA expression following subchronic inhalation exposure. Clin Exp Allergy. 2016; 46(10):1315–1327. 10.1111/cea.12783 27473664
102 Nayak AP, Green BJ, Lemons AR, Marshall NB, Goldsmith WT, Kashon ML, Anderson SE, Germolec DR, Beezhold DH. Subchronic exposures to fungal bioaerosols promotes allergic pulmonary inflammation in naïve mice. Clin Exp Allergy. 2016; 46(6):861–870. 10.1111/cea.12724 26892490
103 Raabe OG, Al-Bayati MA, Teague SV, Rasolt A. Regional deposition of inhaled monodisperse coarse and fine aerosol particles in small laboratory animals. Ann Occup Hyg. 1988; 32 Suppl 1(Inhaled Particles VI):53–63. 10.1093/annhyg/32.inhaled_particles_VI.53
104 National Toxicology Program (NTP). Specifications for the conduct of studies to evaluate the toxic and carcinogenic potential of chemical, biological and physical agents in laboratory animals for the National Toxicology Program (NTP). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health, National Toxicology Program; 2011.
105 Boorman GA, Haseman JK, Waters MD, Hardisty JF, Sills RC. Quality review procedures necessary for rodent pathology databases and toxicogenomic studies: The National Toxicology Program experience. Toxicol Pathol. 2002; 30(1):88–92. 10.1080/01926230252824752 11890481
106 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
107 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
108 Tukey JW. Comparing individual means in the analysis of variance. Biometrics. 1949; 5(2):99–114. 10.2307/3001913 18151955
109 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
110 Dixon WJ, Massey FJ. Introduction to statistical analysis. 2nd ed. New York, NY: McGraw Hill; 1957. p. 145–147, 276–278, 412.
111 U.S. Food and Drug Administration (FDA). 21 CFR Part 58. https://www.accessdata.fda.gov/scripts/cdrh/cfdocs/cfcfr/CFRSearch.cfm?CFRPart=58
112 National Institute for Occupational Safety and Health (NIOSH). NIOSH Health Effects Laboratory Division (HELD) fact sheet. Cincinnati, OH: U.S. Department of Health and Human Services, Public Health Service, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 2019. DHHS (NIOSH) Publication No. 2019-134. 10.26616/NIOSHPUB2019134
113 Miller JA, Miller EC. Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH, Watson JD, Winsten JA, editors. Origins of Human Cancer. Cold Spring Harbor, NY: Cold Spring Harbor Laboratory; 1977. p. 605–627.
114 Straus DS. Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981; 67(2):233–241. 7021938
115 Crawford BD. Perspectives on the somatic mutation model of carcinogenesis. In: Flamm WG, Lorentzen RJ, editors. Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton, NJ: Princeton Scientific Publishing; 1985. p. 13–59.
116 Schmid W. The micronucleus test. Mutat Res. 1975; 31(1):9–15. 10.1016/0165-1161(75)90058-8 48190
117 Heddle JA, Hite M, Kirkhart B, Mavournin K, MacGregor JT, Newell GW, Salamone MF. The induction of micronuclei as a measure of genotoxicity: A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983; 123(1):61–118. 10.1016/0165-1110(83)90047-7 6888413
118 Shelby MD, Erexson GL, Hook GJ, Tice RR. Evaluation of a three-exposure mouse bone marrow micronucleus protocol: Results with 49 chemicals. Environ Mol Mutagen. 1993; 21(2):160–179. 10.1002/em.2850210210 8444144
119 Shelby MD, Witt KL. Comparison of results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutagen. 1995; 25(4):302–313. 10.1002/em.2850250407 7607185
120 Witt KL, Knapton A, Wehr CM, Hook GJ, Mirsalis J, Shelby MD, MacGregor JT. Micronucleated erythrocyte frequency in peripheral blood of B6C3F(1) mice from short-term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutagen. 2000; 36(3):163–194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P 11044899
121 National Toxicology Program (NTP). TOX-107: Pathology tables, survival and growth curves from NTP short-term and genetic toxicology studies. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2024. 10.22427/NTP-DATA-TOX-107
122 Li DW, Yang CS. Taxonomic history and current status of Stachybotrys chartarum and related species. Indoor Air. 2005; 15 Suppl 9:5–10. 10.1111/j.1600-0668.2005.00339.x 15910524
123 Roe JD, Haugland RA, Vesper SJ, Wymer LJ. Quantification of Stachybotrys chartarum conidia in indoor dust using real time, fluorescent probe-based detection of PCR products. J Expo Anal Environ Epidemiol. 2001; 11(1):12–20. 10.1038/sj.jea.7500147 11246797
124 Osimitz TG, Droege W, Finch JM. Toxicologic significance of histologic change in the larynx of the rat following inhalation exposure: A critical review. Toxicol Appl Pharmacol. 2007; 225(3):229–237. 10.1016/j.taap.2007.08.027 17991503
125 Nagayoshi M, Tada Y, West J, Ochiai E, Watanabe A, Toyotome T, Tanabe N, Takiguchi Y, Shigeta A, Yasuda T, et al. Inhalation of Stachybotrys chartarum evokes pulmonary arterial remodeling in mice, attenuated by Rho-kinase inhibitor. Mycopathologia. 2011; 172(1):5–15. 10.1007/s11046-011-9400-3 21505873
126 Rosenblum Lichtenstein JH, Molina RM, Donaghey TC, Hsu YHH, Mathews JA, Kasahara DI, Park JA, Bordini A, Godleski JJ, Gillis BS, et al. Repeated mouse lung exposures to Stachybotrys chartarum shift immune response from type 1 to type 2. Am J Respir Cell Mol Biol. 2016; 55(4):521–531. 10.1165/rcmb.2015-0291OC 27148627
127 Leino M, Mäkelä M, Reijula K, Haahtela T, Mussalo-Rauhamaa H, Tuomi T, Hintikka EL, Alenius H. Intranasal exposure to a damp building mould, Stachybotrys chartarum, induces lung inflammation in mice by satratoxin-independent mechanisms. Clin Exp Allergy. 2003; 33(11):1603–1610. 10.1046/j.1365-2222.2003.01808.x 14616875
128 Rao CY, Burge HA, Brain JD. The time course of responses to intratracheally instilled toxic Stachybotrys chartarum spores in rats. Mycopathologia. 2000; 149(1):27–34. 10.1023/A:1007239017018 11227851
129 Rosenblum Lichtenstein JH, Molina RM, Donaghey TC, Brain JD. Strain differences influence murine pulmonary responses to Stachybotrys chartarum. Am J Respir Cell Mol Biol. 2006; 35(4):415–423. 10.1165/rcmb.2005-0483OC 16690987
130 Innes JR, Ulland BM, Valerio MG, Petrucelli L, Fishbein L, Hart ER, Pallotta AJ, Bates RR, Falk HL, Gart JJ, et al. Bioassay of pesticides and industrial chemicals for tumorigenicity in mice: A preliminary note. J Natl Cancer Inst. 1969; 42(6):1101–1114. 5793189
131 Shimodaira K, Okubo Y, Ochiai E, Nakayama H, Katano H, Wakayama M, Shinozaki M, Ishiwatari T, Sasai D, Tochigi N, et al. Gene expression analysis of a murine model with pulmonary vascular remodeling compared to end-stage IPAH lungs. Respir Res. 2012; 13(1):103. 10.1186/1465-9921-13-103 23157700
132 Hudson B, Flemming J, Sun G, Rand TG. Comparison of immunomodulator mRNA and protein expression in the lungs of Stachybotrys chartarum spore-exposed mice. J Toxicol Environ Health A. 2005; 68(15):1321–1335. 10.1080/15287390590953572 16020192
133 Rand TG, White K, Logan A, Gregory L. Histological, immunohistochemical and morphometric changes in lung tissue in juvenile mice experimentally exposed to Stachybotrys chartarum spores. Mycopathologia. 2003; 156(2):119–131. 10.1023/A:1022920205355 12733633
134 Brain JD, Sieber NL, Rosenblum Lichtenstein JH. Killing two birds with one stone: Mold-induced pulmonary immune responses and arterial remodeling. Am J Respir Cell Mol Biol. 2020; 62(5):537–538. 10.1165/rcmb.2019-0386ED 31693387
135 Witt KL, Livanos E, Kissling GE, Torous DK, Caspary W, Tice RR, Recio L. Comparison of flow cytometry-and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008; 649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571