# Discussion

Stachybotrys chartarum is a hydrophilic fungus that requires a cellulose-rich substrate and a high moisture content for optimal growth.^35-38^ This species is often identified in water-damaged indoor environments and has a worldwide distribution.^35-38,122^ Following infant acute idiopathic pulmonary hemorrhage cases,^14^ as well as the association with “sick building syndrome” and damp building-related illness,^44,46,59,62-66^ the adverse health effects following S. chartarum exposure have become a concern for public health. S. chartarum phialides produce conidia (spores) within a slime droplet that protects the conidia over a long period and inhibits aerosolization. Once dried, the conidia, hyphae, and fragments may be aerosolized within the breathing zone following abiotic or biotic disturbances. While most S. chartarum conidia are too large to deposit deep within the murine lung, this is not the case with the small respirable-size fungal fragments present within this test article.

Although mycotoxicosis and pulmonary immunological endpoints have been previously examined,^29,101^ the systemic toxicity following subchronic inhalation of viable S. chartarum remains undercharacterized. To evaluate the toxicological responses to S. chartarum, groups of 10 male and 10 female B6C3F1/N mice inhaled viable S. chartarum conidia, heat-inactivated S. chartarum conidia (biological particle control), or high-efficiency particulate air [filter] (HEPA)-filtered air (control) twice a week for 3 months. An estimated pulmonary dose of 1 × 10^4^ S. chartarum conidia (viable and heat-inactivated conidia) was chosen for this study, which was the highest aerosolized dose that reproducibly induced a lymphoproliferative response and was the same concentration and schedule used for a previously published pulmonary immunology study.^27^ This estimated lung burden would be equivalent to that of a worker breathing a constant workplace air concentration of 3.45 × 10^6^ conidia/m^3^ (146 μg/m^3^) for 1 week, working 8 hours per day for 5 days or equivalent to a worker breathing 2.3 × 10^4^ conidia/m^3^ (0.97 μg/m^3^) for 8 hours per day, 5 days per week over a 40-year working career. This concentration is comparable to the occupational exposure concentration of 10^3^–10^7^ conidia/m^3^, which has been reported to result in toxicosis.^43^ In addition, studies involving S. chartarum-contaminated residences have also reported spore concentrations around 4 × 10^3^ conidia/m^3^ during remediation^86^ and 10^3^ conidia/mg of dust collected from contaminated areas.^123^

In the current study, inhalation exposure to an estimated pulmonary dose of 1 × 10^4^ viable S. chartarum conidia twice a week for 3 months did not elicit overt toxicity or result in >10% body weight loss compared to the air control group for male or female mice. Additionally, the terminal body weights of mice exposed to either viable S. chartarum or the heat-inactivated particle control were not significantly different from those of the air control group. Although not significant, the absolute and relative lung weights of male mice exposed to viable S. chartarum were slightly higher compared to the air control group, whereas the viable S. chartarum-exposed female mice had significantly increased absolute and relative lung weights compared to the air control group.

No gross lesions were present following exposure; however, the incidences of nonneoplastic lesions were significantly increased in mice exposed to viable S. chartarum. These histopathological changes were evident in the lung and, to a lesser extent, in the larynx and bronchial lymph nodes of viable S. chartarum-exposed mice. Within the rest of the respiratory tract, no histopathological changes were observed in the nose or trachea. In the larynx of both male and female viable S. chartarum-exposed mice, the incidence of squamous metaplasia at the base of the epiglottis was significantly increased compared to the air control mice. In addition, squamous metaplasia at the base of the epiglottis was also observed in the larynx of three female mice exposed to the heat-inactivated particle control. The squamous metaplasia of the larynx epithelium at the base of the epiglottis included replacement of ciliated cuboidal to columnar cells with nonkeratinized stratified squamous epithelium, which is in response to chronic irritation elicited from the viable S. chartarum exposure. The National Toxicology Program (NTP) study detailing the toxicological responses following a subchronic Aspergillus fumigatus exposure also reported similar laryngeal squamous metaplasia at the base of the epiglottis in mice exposed to viable A. fumigatus.^30^ Literature has suggested that the larynx is the site that often responds to repeated inhalation of substances, including fungi, and that the resultant squamous metaplasia is frequently of minimal severity.^30,124^ Additionally, in the bronchial lymph node, lymphocyte hyperplasia was observed in two viable S. chartarum-exposed female mice, but no lesions were observed in S. chartarum-exposed male mice or in the bronchial lymph nodes of air control or heat-inactivated particle control mice.

Histopathological analysis of the lungs of viable S. chartarum-exposed males and females showed nonneoplastic lesions, including perivascular chronic-active inflammation, histiocytic cellular infiltration, medial hypertrophy of pulmonary arteries, thrombi in arteries with medial hypertrophy, hyperplasia of bronchiolar epithelium, goblet cell metaplasia, and bronchus-associated lymphoid tissue (BALT) lymphocyte hyperplasia. The mild to moderate medial hypertrophy affected small- and medium-sized pulmonary arteries and was characterized by circumferential thickening of the tunica media and luminal narrowing and was accompanied by accumulations of inflammatory cells. Intravascular thrombi, which were present in three males and one female exposed to S chartarum, were observed in very low numbers of arterioles that were remodeled as a result of medial hypertrophy. Despite the low incidence and number of affected vessels, the thrombi were considered likely exposure related because they were associated with vascular changes of luminal narrowing and medial hypertrophy. Similar to the current study, previously reported S. chartarum exposure via inhalation (twice per week for 4 weeks or 3 months) in female B6C3F1/N mice resulted in peribronchiolar and perivascular inflammation, alveolar histiocytosis, bronchiolar epithelial cell hyperplasia, as well as pulmonary arterial remodeling characterized by the thickening of the pulmonary arterial wall and narrowing of the lumen.^27^ Neither the air control nor heat-inactivated particle control groups in this study, as well as the previously published pulmonary immunology exposure study,^27^ presented evidence of medial hypertrophy of arteries. In addition, separate studies showed the development of pulmonary arterial hypertension in mice following repeated intratracheal instillation of S. chartarum,^25,125^ accompanied by significantly increased right ventricular systolic pressure and right ventricular hypertrophy in exposed male ddY mice compared to the control mice.^25^ Although cardiac function and pathology were not evaluated in the current study, the heart weights of the S. chartarum-exposed mice were not significantly different compared to the air control group, which is in contrast to the study conducted by Ochiai et al.^25^ These divergent results could be explained by the difference in delivery methods or the difference in mouse or fungal strain. Interestingly, cessation of S. chartarum exposure via intratracheal instillation resulted in the resolution of the pulmonary remodeling^125^; however, further investigation is warranted to determine whether this resolution occurs following repeated inhalation of viable S. chartarum conidia.

In comparison to the current study, an NTP study conducted in collaboration with the National Institute for Occupational Safety and Health (NIOSH) describing the toxicological responses following a subchronic viable A. fumigatus exposure showed similar pulmonary arterial medial hypertrophy.^30^ In addition, chronic-active inflammation, defined as the increased presence of neutrophils and perivascular infiltrates, including alveolar macrophages and eosinophils, was observed in mice exposed to viable A. fumigatus,^30^ and similar cell populations were observed following subchronic viable S. chartarum exposure. The significantly increased eosinophils observed in male mice may correspond to the chronic-active inflammation in the lung following subchronic viable S. chartarum exposure.

Perivascular chronic-active inflammation observed in the current study was characterized by an influx of inflammatory cell populations, including lymphocytes, neutrophils, eosinophils, and macrophages in the pulmonary arterial walls with extension into the immediately adjacent interstitial tissue and alveoli. In addition, histiocytic cellular infiltrates were observed in all viable S. chartarum-exposed male and female mice. All findings were also observed in female B6C3F1/N mice in a previously published study, following a 3-month exposure of viable S. chartarum via inhalation.^27^ Croston and colleagues showed, in the analysis of the bronchoalveolar lavage fluid (BALF), a significant increase in neutrophils, macrophages, and eosinophils at 24 hours and 48 hours post final exposure following a 3-month exposure to S. chartarum.^27^ In agreement, Nagayoshi et al. showed a significant increase in eosinophils accompanied by high concentrations of T helper 2 cell (Th2)-associated cytokines, interleukin (IL)-4 and IL-5, in the BALF following a 12-week intratracheal instillation of S. chartarum in male ddY mice.^125^ Using male BALB/c mice, Rosenblum Lichtenstein and colleagues also showed significantly increased BALF neutrophils, lymphocytes, and eosinophils and significantly increased IL-4, IL-5, and IL-6, supporting a Th2 response following a 7-week S. chartarum intratracheal instillation.^126^ Using the same mouse strain, Leino et al. reported significantly increased inflammatory cells including monocytes, neutrophils, and lymphocytes in response to intranasal instillation (twice a week for 3 weeks) of 1 × 10^5^ satratoxin-producing and nonsatratoxin-producing S. chartarum spores in female mice.^127^ No inflammatory cellular infiltrates were observed following exposure to 1 × 10^3^ satratoxin-producing and nonsatratoxin-producing S. chartarum spores.^127^ Additionally, proinflammatory cytokines were induced in the lungs of S. chartarum-exposed mice,^127^ and in contrast to previously published data,^125,126^ there was no significant increase in the expression of hallmark Th1 or Th2 cytokines. Although cytokine expression was not measured in the current study, Croston and colleagues showed that a 4-week exposure to viable S. chartarum resulted in a Th2-mediated response that switched to a mixed T-cell response after 3 months of exposure, as evidenced by significantly increased ifng (interferon-gamma; IFN-γ), il2 (IL-2), and il13 (IL-13) gene expression in the lungs of exposed mice.^27^ This mixed T-cell response is in contrast to other literature reporting a Th2-mediated response following 7 weeks^126^ and 12 weeks^125^ of S. chartarum exposure and, as previously stated, could be due to the difference in exposure methods or the different mouse and fungal strains used for the studies. While literature describes the evidence of Th2-mediated pulmonary arterial remodeling after 12 weeks of S. chartarum exposure,^25,27,125^ this pathological observation has been observed as early as 4 weeks following exposure to the same exposure schedule and strain of S. chartarum used in the current study.^27^ Ochiai et al.^25^ reported the development of pulmonary arterial thickening in S. chartarum-exposed mice after 4 weeks of intratracheal instillation. Previous studies suggest that the duration of S. chartarum exposures,^27,126^ the route of delivery,^23-26,128^ fungal strain,^27^ and the animal model employed^129^ could influence the resulting immune responses and lung pathologies.

Studies have indicated that different strains of mice respond differently following S. chartarum exposure.^129^ Specifically, BALB/c (Th2-biased) mice showed a different lung injury profile and inflammatory-associated biochemical and cellular profile than C57BL/6J (Th1-biased)^126,129^ and C3H/HeJ mice.^129^ The hybrid B6C3F1/N mouse strain used in the current study has been widely used to study systemic toxicological responses and was selected for consistency with other NTP toxicology studies. This strain is resistant to disease and has low spontaneous disease rates compared with other strains and hybrids.^130^ Although the female parent of the hybrid B6C3F1/N mouse strain, C57BL/6, is Th1-biased, histopathological results of the airways are consistent with previously observed histopathology in other strains of mice, including ddY mice.^25^ Moreover, the ddY mouse strain has been previously used as a model of S. chartarum-induced idiopathic pulmonary arterial hypertension.^131^ For the studies using the ddY mouse model, the S. chartarum test article was administered via intratracheal instillation.^25,125,131^ Compared to intratracheal and intranasal instillation or liquid aerosol inhalation that deliver conidia in a liquid suspension,^23-26,128^ which can potentially modify the viability and components of the conidia,^42^ the current study used a previously developed system to deliver dry aerosolized conidia to mice housed in nose-only exposure chambers, simulating a natural exposure that could be experienced in a S. chartarum-contaminated environment. Although the S. chartarum test article in the current study was not grown on building materials as has been previously used, the use of rice as a nutrient-rich growth substrate eliminates the potential interference of building material exposure to the mice housed in the exposure units. These differences in the administration of the S. chartarum conidia could partly account for the contrasting results observed among the different exposure studies. In addition, the strain of S. chartarum used in the study may also be a parameter that could influence the pulmonary responses following repeated exposure. As previously reported,^27^ a higher-fragmenting strain of S. chartarum (IBT 9460) elicited an earlier pulmonary immune response and pulmonary arterial remodeling compared to a lesser fragmenting strain of S. chartarum (IBT 7711), indicating that smaller fragments may deposit deeper in the lungs and induce these responses. Therefore, the higher-fragmenting S. chartarum strain (IBT 9460) was selected for toxicological evaluation in the current study. Furthermore, the cultivation and aerosolization of IBT 9460 has been previously optimized.^28^ In the study conducted by Lemons et al., both the viable S. chartarum test article (IBT 9460) and the heat-inactivated particle control contained similar levels of verrucarol, a hydrolysis product of macrocyclic trichothecene, which were four times higher than the S. chartarum (IBT 7711) strain. In addition, the endotoxin level of the viable S. chartarum test article was near or below the limit of detection.^28^

In the current 3-month study, very low numbers of conidia were observed free in the alveoli or within alveolar macrophages of most viable S. chartarum-exposed mice (Figure 9) and in the bronchial lymph node of two viable S. chartarum-exposed female mice. Following a 4-week intratracheal instillation of S. chartarum spores in male ddY mice, spores were shown to be present for only 24 hours before being cleared by alveolar macrophages.^125^ In addition, fungal components were not visualized in left lung lobes following a 3-month inhalation exposure to S. chartarum in female B6C3F1 mice,^27^ which is contrary to the histopathological observations of the current study. Similar to the current study, A. fumigatus spores were detected within the lungs of mice following exposure; however, in a few cases, swollen conidia and germ tubes were detected, indicating active germination of the conidia,^30,100,102^ which was not observed in the current study.

Hyphal fragments can also be aerosolized within an indoor environment following abiotic or biotic disturbance. Studies have demonstrated that fungal fragments contribute to the fungal biomass within indoor environments.^10,11^ Studies of S. chartarum have predicted that fragments can be aerosolized at particle concentrations 500 times higher than spores.^8^ Furthermore, deposition of submicron fungal fragments deep within the human respiratory tract is 230–250 fold higher than that of spores, which would primarily be deposited in the upper respiratory tract.^8^ Croston and colleagues have recently proposed fragments as the primary driver of pulmonary immune responses following the inhalation of S. chartarum.^27^ Moreover, literature has suggested that the macrocyclic trichothecenes detected on S. chartarum fragments may contribute to the toxigenic health effects following exposure.^37,47^ In addition to macrocyclic trichothecenes, other biologically active products of S. chartarum, such as hemolysins, proteinases, glucans, and volatile organic compounds, could act in concert to contribute to the toxigenic health effects following exposure.^37^ A study conducted by Hudson et al. demonstrated pulmonary immune response differences in the magnitude and temporal interval following intratracheal instillation exposure to conidia of macrocyclic-trichothecene-producing (JS 58-17) and nonproducing chemotype (JS 58-06) S. chartarum.^132^ Additionally, Rand and colleagues determined that pulmonary tissue collected from CFW male mice following a single intratracheal instillation of S. chartarum spores responds differently compared to pure trichothecene exposure (isosatratoxin F), including significantly decreased alveolar air space and significantly increased erythrocytes in the intra-alveolar air space.^133^ Although mycotoxin profiles and concentrations were not evaluated in the current study, Lemons et al. showed similar levels of verrucarol in the viable and heat-inactivated particle control aerosols of the same strain of S. chartarum.^28^ Furthermore, Croston et al. showed that a more rapid immune response and pulmonary remodeling occurred following exposure to this higher-fragmenting and mycotoxin-producing strain of S. chartarum (IBT 9460).^27^ As the peer-reviewed literature has suggested, fragment size, mycotoxin content, or a combination of these factors could be responsible for the immune response and arterial remodeling observed; therefore, further research is warranted.^134^

Findings from the current 3-month inhalation study in B6C3F1/N mice included significantly increased absolute and relative lung weights in viable S. chartarum-exposed female mice, relative to the heat-inactivated control and air control groups accompanied by significantly increased incidences of nonneoplastic lesions. In males and females exposed to viable S. chartarum, nonneoplastic lesions were restricted mainly to the larynx and lung; however, there was also a low incidence of lymphocyte hyperplasia in the bronchial lymph nodes of viable S. chartarum-exposed female mice. In the larynx, nonneoplastic lesions consisted of squamous metaplasia of the epithelium localized at the base of the epiglottis. Lung histopathology findings were composed of several lesions, including medial hypertrophy of the pulmonary arteries/arterioles in viable S. chartarum-exposed mice but not in heat-inactivated particle control mice. These results correspond with the results from a previously published subchronic S. chartarum pulmonary immunology study conducted by NIOSH with the same exposure system that showed Th2-mediated pulmonary inflammation and pulmonary arterial remodeling after subchronic S. chartarum inhalation exposure.^27^ The results of the current study were also similar to the previously published NTP report detailing the toxicological responses to A. fumigatus exposure in which the incidence of nonneoplastic lesions was significantly increased in the larynx, lung, and bronchial lymph nodes of viable A. fumigatus-exposed mice.^30^ Specifically, the incidences of bronchial lymphocytic hyperplasia and plasma cell hyperplasia were significantly increased in viable A. fumigatus-exposed mice but not in viable S. chartarum-exposed mice, relative to either the air control or the heat-inactivated particle control groups.^30^ In both the current study of S. chartarum and the previously published NTP report of A. fumigatus, lungs of mice exposed to viable conidia displayed inflammation, medial hypertrophy of pulmonary arterioles and arteries, bronchiolar epithelium hyperplasia, goblet cell metaplasia, BALT lymphocyte hyperplasia, and the presence of very low numbers of conidia.

Under the conditions of this 3-month study, target organs identified in B6C3F1/N mice following inhalation exposure to viable S. chartarum conidia were the larynx, lung, and (to a lesser extent) the bronchial lymph nodes. The histopathological changes observed following viable S. chartarum exposure were not seen in the heat-inactivated particle control or air control mice. These results build on initial pulmonary immunology studies conducted at NIOSH using the same exposure parameters and demonstrate that the immunological responses and histopathology could be mediated by the viable S. chartarum bioaerosol.