# Results

## Data Availability

All study data were evaluated. Data relevant for evaluating toxicological findings are presented here. All study data are available in the National Toxicology Program (NTP) Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TOX-107.^121^

## Three-month Study

All female mice survived to the end of the study. One male mouse in the air control group suffered a hind limb wound and was euthanized on day 8 of exposure. All tissues defined in Table 1 were collected from all 10 males and 10 females following necropsy.

Final survival and body weight data are shown in Table 2 and Table 3. Terminal body weights of male and female mice exposed to viable S. chartarum conidia (spores) were not significantly different from the air control or the heat-inactivated particle control groups, nor were terminal body weights significantly different between the heat-inactivated particle control and air control groups. The body weight gain among groups of both male and female mice over the course of the study was similar, as illustrated in Figure 5. Clinical observations collected throughout the duration of the study revealed no remarkable findings (Appendix E).

Table 2 Summary of Survival and Body Weights of Male Mice in the Three-month Inhalation Study of Stachybotrys chartarum

Study Day^a^ | Air Control | | Heat-inactivated Particle Control | | | Viable S. chartarum
Study Day^a^ | Wt. (g)^b,c^ | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n
1 | 24.6 ± 0.4 | 10 | 25.0 ± 0.4 | 101.7 | 10 | 24.5 ± 0.4 | 99.7 | 10
8 | 24.8 ± 0.4 | 9^d^ | 25.1 ± 0.4 | 101.1 | 10 | 24.5 ± 0.4 | 98.7 | 10
15 | 25.8 ± 0.5 | 9 | 26.1 ± 0.4 | 101.1 | 10 | 25.4 ± 0.5 | 98.8 | 10
22 | 26.4 ± 0.4 | 9 | 26.6 ± 0.5 | 100.8 | 10 | 26.2 ± 0.5 | 99.5 | 10
29 | 26.8 ± 0.4 | 9 | 27.3 ± 0.6 | 101.7 | 10 | 27.1 ± 0.5 | 100.8 | 10
36 | 29.2 ± 0.6 | 9 | 29.5 ± 0.8 | 101.0 | 10 | 29.0 ± 0.6 | 99.3 | 10
43 | 28.6 ± 0.5 | 9 | 29.1 ± 0.7 | 101.7 | 10 | 28.8 ± 0.7 | 100.6 | 10
50 | 29.3 ± 0.6 | 9 | 30.0 ± 0.8 | 102.2 | 10 | 29.6 ± 0.7 | 100.8 | 10
58 | 30.4 ± 0.6 | 9 | 31.0 ± 0.8 | 102.2 | 10 | 30.7 ± 0.7 | 101.0 | 10
64 | 31.7 ± 0.6 | 9 | 31.9 ± 0.8 | 100.5 | 10 | 32.0 ± 0.7 | 100.8 | 10
71 | 32.2 ± 0.5 | 9 | 32.7 ± 0.8 | 101.5 | 10 | 32.6 ± 0.7 | 101.1 | 10
78 | 32.9 ± 0.6 | 9 | 33.5 ± 0.9 | 101.8 | 10 | 33.4 ± 0.7 | 101.6 | 10
85 | 33.2 ± 0.7 | 9 | 33.7 ± 0.9 | 101.5 | 10 | 34.1 ± 0.7 | 102.8 | 10
88 | 33.3 ± 0.6 | 9 | 33.4 ± 0.9 | 101.5 | 10 | 33.9 ± 0.8 | 101.7 | 10

^a^ Study day 1 is the day animals were placed on study.

^b^ Statistical analysis performed using one-way analysis of variance with post hoc Tukey Honest Significant Difference test for all pairwise comparisons. No statistically significant findings were noted at p ≤ 0.05.

^c^ Weights shown are mean ± standard error.

^d^ One male in the air control group was euthanized on study day 8 due to a hind leg wound.

Table 3 Summary of Survival and Body Weights of Female Mice in the Three-month Inhalation Study of Stachybotrys chartarum

Study Day^a^ | Air Control | | Heat-inactivated Particle Control | | | Viable S. chartarum
Study Day^a^ | Wt. (g)^b,c^ | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n
1 | 21.2 ± 0.5 | 10 | 21.3 ± 0.2 | 100.6 | 10 | 21.3 ± 0.3 | 100.4 | 10
8 | 21.5 ± 0.5 | 10 | 21.8 ± 0.3 | 101.4 | 10 | 21.6 ± 0.3 | 100.4 | 10
15 | 22.4 ± 0.6 | 10 | 22.7 ± 0.3 | 101.7 | 10 | 22.3 ± 0.5 | 99.6 | 10
22 | 23.1 ± 0.7 | 10 | 23.7 ± 0.3 | 102.6 | 10 | 23.1 ± 0.6 | 100.3 | 10
29 | 23.6 ± 0.8 | 10 | 24.6 ± 0.5 | 104.2 | 10 | 23.7 ± 0.6 | 100.2 | 10
36 | 25.4 ± 1.1 | 10 | 27.2 ± 0.5 | 107.3 | 10 | 24.5 ± 0.8 | 96.7 | 10
43 | 25.2 ± 1.1 | 10 | 27.5 ± 0.5 | 108.9 | 10 | 24.6 ± 0.8 | 97.4 | 10
50 | 26.1 ± 1.2 | 10 | 28.2 ± 0.5 | 108.1 | 10 | 25.0 ± 0.9 | 96.0 | 10
58 | 27.0 ± 1.2 | 10 | 29.1 ± 0.6 | 107.9 | 10 | 25.9 ± 1.0 | 96.0 | 10
64 | 27.9 ± 1.4 | 10 | 30.0 ± 0.7 | 107.4 | 10 | 26.8 ± 1.0 | 95.8 | 10
71 | 28.8 ± 1.3 | 10 | 30.7 ± 0.6 | 106.3 | 10 | 27.5 ± 1.1 | 95.3 | 10
78 | 29.7 ± 1.3 | 10 | 31.9 ± 0.8 | 107.2 | 10 | 29.0 ± 1.0 | 97.5 | 10
85 | 30.3 ± 1.3 | 10 | 32.5 ± 0.8 | 107.3 | 10 | 29.6 ± 1.0 | 97.6 | 10
88 | 30.2 ± 1.2 | 10 | 32.1 ± 0.8 | 106.2 | 10 | 29.4 ± 1.1 | 97.4 | 10

^a^ Study day 1 is the day animals were placed on study.

^b^ Statistical analysis performed using one-way analysis of variance with post hoc Tukey Honest Significant Difference test for all pairwise comparisons. No statistically significant findings were noted at p ≤ 0.05.

^c^ Weights shown are mean ± standard error.

Figure 5

Growth Curves for Male and Female Mice in the Three-month Inhalation Study of Stachybotrys chartarum

Growth curves are shown for (A) males and (B) females.

A minimal but significant decrease (<1.3%) in mean cell volume was observed in the viable S. chartarum-exposed male mice compared to the air control and heat-inactivated particle control groups (Appendix E). This change was not observed in the viable S. chartarum-exposed female mice and was not considered exposure related. Eosinophil counts were significantly increased in the viable S. chartarum-exposed male mice relative to the air control and heat-inactivated particle control groups (Table 4). Although not significant, eosinophil counts were higher in the viable S. chartarum-exposed female mice relative to the air control and heat-inactivated particle control groups.

Table 4 Summary of Select Hematology Data for Male and Female Mice in the Three-month Inhalation Study of Stachybotrys chartarum

Endpoint^a,b^ | Air Control | Heat-inactivated Particle Control | Viable S. chartarum
Male
n | 9 | 9^c^ | 10
Leukocytes (10^3^/µL) | 3.25 ± 0.29 | 3.84 ± 0.20 | 3.77 ± 0.38
Neutrophils (10^3^/µL) | 0.58 ± 0.04 | 0.63 ± 0.06 | 0.48 ± 0.04
Lymphocytes (10^3^/µL) | 2.52 ± 0.25 | 3.03 ± 0.16 | 2.96 ± 0.34
Monocytes (10^3^/µL) | 0.03 ± 0.01 | 0.03 ± 0.00 | 0.08 ± 0.04
Eosinophils (10^3^/µL) | 0.12 ± 0.01 | 0.14 ± 0.03 | 0.25 ± 0.03^**##^
Basophils (10^3^/mL) | 0.00 ± 0.00 | 0.01 ± 0.00 | 0.01 ± 0.00
Female
n | 6^c^ | 9^c^ | 7^c^
Leukocytes (10^3^/µL) | 2.44 ± 0.40 | 1.88 ± 0.32 | 2.57 ± 0.31
Neutrophils (10^3^/µL) | 0.70 ± 0.11 | 0.59 ± 0.22 | 0.67 ± 0.13
Lymphocytes (10^3^/µL) | 1.66 ± 0.43 | 1.20 ± 0.20 | 1.74 ± 0.29
Monocytes (10^3^/µL) | 0.02 ± 0.01 | 0.01 ± 0.00 | 0.05 ± 0.01
Eosinophils (10^3^/µL) | 0.06 ± 0.01 | 0.07 ± 0.01 | 0.11 ± 0.02
Basophils (10^3^/mL) | 0.01 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00

** Statistically significant pairwise difference from air control at p ≤ 0.01.

^##^ Statistically significant pairwise difference from heat-inactivated particle control at p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Dunn (pairwise) test.

^c^ N values differ from number of animals due to insufficient amount of collected sample or coagulation of blood before analysis.

Absolute and relative lung weights were significantly increased in viable S. chartarum-exposed female mice compared to the air control group (33% and 35%, respectively) (Table 5). Although not significant, the absolute and relative lung weights of male mice exposed to viable S. chartarum were also higher compared to the air control mice (11% and 5%, respectively) (Table 5).

Table 5 Summary of Lung Weights and Lung-Weight-to-Body-Weight Ratios of Male and Female Mice in the Three-month Inhalation Study of Stachybotrys chartarum

Endpoint^a,b^ | Air Control | Heat-inactivated Particle Control | Viable S. chartarum
Male
n | 9 | 10 | 10
Necropsy Body Wt. (g) | 33.3 ± 0.6 | 33.4 ± 0.9 | 33.9 ± 0.8
Lung
Absolute (g) | 0.18 ± 0.01 | 0.19 ± 0.01 | 0.20 ± 0.01
Relative (mg/g)^c^ | 5.50 ± 0.25 | 5.72 ± 0.17 | 5.80 ± 0.20
Female
n | 10 | 10 | 10
Necropsy Body Wt. (g) | 30.2 ± 1.2 | 32.1 ± 0.8 | 29.4 ± 1.1
Lung
Absolute (g) | 0.18 ± 0.01 | 0.17 ± 0.01 | 0.24 ± 0.01**^##^
Relative (mg/g) | 6.07 ± 0.36 | 5.31 ± 0.29 | 8.17 ± 0.40**^##^

** Statistically significant pairwise difference from air control at p ≤ 0.01.

^##^ Statistically significant pairwise difference from heat-inactivated particle control at p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed using one-way analysis of variance with post hoc Tukey Honest Significant Difference test for all pairwise comparisons.

^c^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

### Histopathology

This section describes the statistically significant or biologically noteworthy changes in the incidences of nonneoplastic lesions of the larynx, lung, and bronchial lymph node.

Gross pathology was evaluated for the organs listed in Table 1. There were no gross lesions identified in any organs evaluated in the male and female groups (Appendix E).

Nonneoplastic lesions in the larynx, lung, and bronchial lymph nodes of viable S. chartarum-exposed male and female mice were present in increased numbers compared to air and heat-inactivated particle control groups (Table 6, Table 7, Table 8). The incidences of nonneoplastic lesions were also higher in the larynx of heat-inactivated particle control-exposed female mice compared to the air control.

Table 6 Incidence of Nonneoplastic Lesions of the Larynx in Male and Female Mice in the Three-month Inhalation Study of Stachybotrys chartarum

| Air Control | Heat-inactivated Particle Control | Viable S. chartarum
Male
n^a^ | 10 | 10 | 10
Epiglottis, Metaplasia, Squamous^b^ | 0 | 0 | 4*^#^ (1.0)^c^
Female
n | 10 | 9 | 10
Epiglottis, Metaplasia, Squamous | 0 | 3 (1.0) | 7** (1.0)

* Statistically significant pairwise difference from air control at p ≤ 0.05; ** p ≤ 0.01.

^#^ Statistically significant pairwise difference from heat-inactivated particle control at p ≤ 0.05.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion. Statistical analysis performed by Fisher’s exact (pairwise) one-sided test.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Table 7 Incidences of Select Nonneoplastic Lesions of the Lung in Male and Female Mice in the Three-month Inhalation Study of Stachybotrys chartarum

| Air Control | Heat-inactivated Particle Control | Viable S. chartarum
n^a^ | 10 | 10 | 10
Male
Perivascular, Inflammation, Chronic-Active^b^ | 0 | 0 | 10**^##^ (2.6)^c^
Artery, Hypertrophy, Medial | 0 | 0 | 10**^##^ (2.4)
Artery, Thrombus | 0 | 0 | 3
Bronchiole, Epithelium, Hyperplasia | 0 | 0 | 10**^##^ (1.1)
BALT, Hyperplasia, Lymphocyte | 0 | 0 | 9**^##^ (1.0)
Infiltration Cellular, Histiocyte | 0 | 0 | 10**^##^ (1.8)
Metaplasia, Goblet Cell | 0 | 0 | 10**^##^ (1.8)
Fungus | 0 | 1 | 9**^##^
Female
Perivascular, Inflammation, Chronic-Active | 0 | 0 | 10**^##^ (2.7)
Artery, Hypertrophy, Medial | 0 | 0 | 10**^##^ (2.9)
Artery, Thrombus | 0 | 0 | 1
Bronchiole, Epithelium, Hyperplasia | 0 | 0 | 10**^##^ (1.0)
BALT, Hyperplasia, Lymphocyte | 0 | 0 | 9**^##^ (1.0)
Infiltration Cellular, Histiocyte | 0 | 0 | 10**^##^ (2.0)
Metaplasia, Goblet Cell | 0 | 0 | 10**^##^ (2.5)
Fungus | 0 | 9** | 10**

** Statistically significant pairwise difference from air control at p ≤ 0.01.

^##^ Statistically significant pairwise difference from heat-inactivated particle control at p ≤ 0.01.

BALT = bronchus-associated lymphoid tissue.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion. Statistical analysis performed by Fisher’s exact (pairwise) one-sided test.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Table 8 Incidences of Select Nonneoplastic Lesions of the Bronchial Lymph Node in Male and Female Mice in the Three-month Inhalation Study of Stachybotrys chartarum

| Air Control | Heat-inactivated Particle Control | Viable S. chartarum
Male
n^a^ | 10 | 10 | 8
Hyperplasia, Lymphocyte^b^ | 0 | 0 | 0
Fungus | 0 | 0 | 0
Female
n | 10 | 8 | 8
Hyperplasia, Lymphocyte | 0 | 0 | 2 (1.0)^c^
Fungus | 0 | 0 | 2

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion. Statistical analysis performed by Fisher’s exact (pairwise) one-sided test. No statistically significant findings were noted at p ≤ 0.05.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

The presence of fungal material in tissue sections was not observed following hematoxylin and eosin staining. Histological sections of aorta, gallbladder, heart, liver, lung, bronchial lymph node, and spleen were stained with Grocott’s methenamine silver (GMS) stain to detect fungal elements. No fungal material was observed in the aorta, gallbladder, heart, liver, or spleen sections.

Larynx: In the larynx of viable S. chartarum-exposed male and female mice, the incidence of squamous metaplasia of the epiglottis was significantly increased compared to the air control (males and females) or heat-inactivated particle control (males) groups (Table 6). Squamous metaplasia of the epiglottis was observed in 3/10 female mice in the heat-inactivated particle control group. The lesions were present at the base of the epiglottis and were characterized by the replacement of normal ciliated cuboidal to columnar epithelium with nonkeratinized squamous epithelium (Figure 6). The metaplasia was graded as minimal (severity score of 1) in all instances and involved <50% of the epithelium overlying the glands at the base of the epiglottis.

Figure 6

Representative Images of Control Larynx and Squamous Metaplasia in the Larynx of Male and Female Mice in the Three-month Inhalation Study of Stachybotrys chartarum (H&E)

Larynx sections from (A) an air control male mouse and (B) a viable S. chartarum-exposed female mouse at the base of the epiglottis (40×). In the air control mouse, the epithelium at the base of the epiglottis has normal ciliated columnar epithelium overlying the seromucinous glands. In the viable S. chartarum-exposed mouse, minimal squamous metaplasia, indicated by the arrowheads, was seen as replacement of the normal ciliated epithelium by nonkeratinized squamous epithelium. H&E = hematoxylin and eosin stain.

Lung: Numerous changes were observed in the lungs of viable S. chartarum-exposed mice compared to the air control and heat-inactivated particle control groups, which both displayed no lesions. Perivascular chronic-active inflammation was evident in all the viable S. chartarum-exposed males and females and was not observed in the air control or heat-inactivated particle control groups (Table 7). Chronic-active inflammation was characterized by the predominantly perivascular accumulations of lymphocytes, neutrophils, eosinophils, and macrophages in pulmonary artery walls, with extension into the immediately surrounding interstitial tissue (Figure 7).

Figure 7

Representative Images of Control Lungs and Perivascular Chronic-Active Inflammation and Medial Hypertrophy of the Pulmonary Artery in the Lungs of Male and Female Mice in the Three-month Inhalation Study of Stachybotrys chartarum (H&E)

Lung sections from (A, C, E) air control mice and (B, D, F) viable S. chartarum-exposed mice. At low magnification (4×), (B) arteries/arterioles and inflammation (arrows) are prominent in the viable S. chartarum-exposed female mouse lung compared to the (A) air control male mouse lung. The (C) normal arteriole from an air control female mouse with thin vessel walls in the lung compared to the (D) arteriole with medial hypertrophy (arrow) in the viable S. chartarum-exposed female mouse with circumferential thickening of the tunica media by concentric layers of hypertrophied and hyperplastic smooth muscle cells and narrowing of the vascular lumen (20×). The (D) viable S. chartarum-exposed female mouse shows perivascular chronic-active inflammation (white asterisk), seen as accumulations of lymphocytes, neutrophils, and eosinophils and histiocytic cellular infiltrates in surrounding alveoli. The (D) bronchiole in the upper left exhibits bronchiole epithelium hyperplasia (arrowhead), as compared to the (E) bronchiole epithelium in a control male mouse (20×). (F) Goblet cell metaplasia (white arrows) was also seen in bronchioles of viable S. chartarum-exposed mice (40×). H&E = hematoxylin and eosin stain.

The perivascular chronic-active inflammation in viable S. chartarum-exposed mice was associated with thickening of the small- and medium-sized pulmonary arteries (medial hypertrophy, Figure 7). Mild to moderate medial hypertrophy of pulmonary arteries was present in all male and female viable S. chartarum-exposed mice and was not observed in the air control or heat-inactivated particle control groups (Table 6). The medial hypertrophy was characterized by circumferential thickening of the tunica media by concentric layers of hypertrophied and hyperplastic smooth muscle cells of the affected artery walls, accompanied by narrowing of the lumens. In three viable S. chartarum-exposed males and one viable S. chartarum-exposed female (Table 6), the artery medial hypertrophy was associated with very low numbers of intravascular thrombi (Figure 8). Medial hypertrophy and perivascular chronic-active inflammation severity was graded based upon the proportion of pulmonary arteries affected as follows: minimal severity (1) was <10% affected, mild (2) was 10%–40% affected, moderate (3) was 41%–75% affected, and marked (4) was >75% affected.

Figure 8

Representative Image of Thrombus in the Lung of a Male Mouse in the Three-month Inhalation Study of Stachybotrys chartarum (H&E)

A thrombus in a small artery in the lung from a viable S. chartarum-exposed mouse. Thrombi were present in very low numbers within arteries exhibiting medial hypertrophy (40×). Chronic-active perivascular inflammation composed of lymphocytes, neutrophils, and eosinophils within and around the vessel wall and histiocyte infiltration in the surrounding alveolar spaces are also present. H&E = hematoxylin and eosin stain.

Bronchiolar epithelial hyperplasia was observed in all viable S. chartarum-exposed male and female mice and was not observed in the air control or heat-inactivated particle control groups (Table 7). Minimal bronchiolar epithelial hyperplasia was characterized by crowded, plump, often piled (2–5 cell layers thick), cuboidal, ciliated epithelial cells lining terminal bronchioles, with extension into adjacent alveolar septa (Figure 7). In most cases, the bronchiolar epithelial hyperplasia involved <10% of bronchioles and was considered minimal (1) but was graded as mild (2) in one male viable S. chartarum-exposed mouse in which 10%–20% of the bronchioles were affected.

Lymphocyte hyperplasia of the bronchus-associated lymphoid tissue (BALT) in the lung was observed in 9/10 viable S. chartarum-exposed males and females and was not observed in the air control or heat-inactivated particle control groups (Table 7). Lymphocyte hyperplasia of the BALT consisted of an increase in the size and/or number of aggregates of lymphocytes adjacent to bronchi when compared with that observed in air control animals. Air control animals had 0 to 1 lymphoid aggregates (most had 0). The severity of BALT lymphocyte hyperplasia was minimal (1) in all cases.

Histiocytic cellular infiltration in the lung was observed in all viable S. chartarum-exposed male and female animals (Table 7). The infiltration was characterized by a minimal to moderate increase in the numbers of diffusely scattered macrophages and rare multinucleated giant cells within alveolar spaces. The lesion severity was graded based upon the proportion of lung affected as follows: minimal severity (1) had <10% of the lung affected, mild (2) had 10%–40% affected, moderate (3) had 41%–75% affected, and marked (4) had >75% affected.

Goblet cell metaplasia was observed in all viable S. chartarum-exposed male and female mice and was not observed in the air control or heat-inactivated particle control groups (Table 7). Goblet cell metaplasia affected most to all of the epithelium in an individual airway and was characterized by increased numbers of goblet cells in the epithelium lining the bronchi and/or bronchioles (Figure 7). The severity of this lesion ranged from minimal to moderate and was graded based upon the proportion of airways affected as follows: minimal (1) had <10% of airways affected, mild (2) had 10%–40% affected, moderate (3) had 41%–75% affected, and marked (4) had >75% affected.

The lung sections of 9/10 male and 10/10 female viable S. chartarum-exposed mice stained positive for fungal material (Table 7). In the heat-inactivated particle control groups, GMS-positive fungal material was also observed in 1/10 male mice and 9/10 female mice (Table 7). GMS-positive structures consistent with viable S. chartarum conidia were observed in very low numbers (usually <5 throughout the entire lung section) and were round to oval, measuring 3 to 6 µm, and observed intracellularly within alveolar macrophages and occasionally free floating within the alveolar spaces (Figure 9).

Figure 9

Representative Images of Fungal Conidia Observed within the Lungs of Female Mice in the Three-month Inhalation Study of Stachybotrys chartarum (GMS)

Grocott’s methenamine silver (GMS)-positive structures consistent with S. chartarum conidia were rarely observed, but, when present, were seen free within (A) alveoli or (B) alveolar macrophages. (A: heat-inactivated particle control lung, 40×. B: viable S. chartarum lung, 40×).

Bronchial lymph node: Bronchial, mandibular, mediastinal, and mesenteric lymph nodes were analyzed in all study mice. Histopathological analysis showed no visible lesions in the mandibular, mediastinal, or mesenteric lymph nodes. In the bronchial lymph node, lymphocyte hyperplasia was observed in two female viable S. chartarum-exposed mice but not in the viable S. chartarum-exposed male mice (Table 8). No lesions were observed in the bronchial lymph nodes of air control or heat-inactivated particle control mice. Lymphocyte hyperplasia was minimal in severity and characterized by increased numbers of lymphocytes within the cortex, paracortex, and medullary regions (Figure 10).

Figure 10

Representative Images of Control Lungs with Bronchial Lymph Node and Lymphocyte Hyperplasia in the Bronchial Lymph Nodes of Female Mice in the Three-month Inhalation Study of Stachybotrys chartarum (H&E)

At the same magnification, the bronchial lymph node from (A) an air control mouse is smaller than the bronchial lymph node from (B) a viable S. chartarum-exposed mouse with lymphocyte hyperplasia, which was seen as increased numbers of lymphocytes in multiple compartments, including the cortex, follicles, paracortex, and medullary cords (2×). H&E = hematoxylin and eosin stain.

Very low numbers of conidia were also observed in the bronchial lymph node of the two female viable S. chartarum-exposed mice that also had lymphocyte hyperplasia of the bronchial lymph node (Table 8).

## Genetic Toxicology

No significant increases in the frequencies of micronucleated reticulocytes and mature erythrocytes were observed in the peripheral blood of male or female B6C3F1/N mice exposed to either viable S. chartarum or heat-inactivated particle control conidia relative to the air control mice (Table D-1). Similarly, no significant increase in frequency was observed in mice exposed to viable S. chartarum conidia compared to mice exposed to the heat-inactivated particle control. In addition, no significant alteration in the percentage of reticulocytes was observed in these mice, suggesting no effects on hematopoiesis. These negative results in the micronucleus test indicate an absence of exposure-induced chromosomal damage in progenitor erythrocytes in the bone marrow of mice, along with an absence of generalized bone marrow toxicity. Data from all NTP genetic toxicity tests with S. chartarum are available in the NTP CEBS database: https://doi.org/10.22427/NTP-DATA-TOX-107.^121^