# Materials and Methods

## Procurement and Characterization

### Culture of Stachybotrys chartarum

Stachybotrys chartarum (CBS 414.95, IBT 9460) was originally isolated from a water-damaged building in Finland.^1^ This is a macrocyclic trichothecene-producing strain and can fragment to a greater extent than other S. chartarum strains.^28^ Bulk S. chartarum cultures were cultivated from 25% glycerol stocks prepared as described in ‎Appendix A. Aliquots of the glycerol stock were stored at −80°C for the study duration.

Individual glycerol stock aliquots were used weekly to inoculate two malt extract agar (MEA) plates for the cultivation of S. chartarum according to the methods detailed in ‎Appendix A. After 12–14 days of culture, S. chartarum conidia (spores) were liberated from each plate using 2 mL of sterile water. Twelve culture flasks containing wet, autoclaved white rice (30 g) were inoculated with 1.25 × 10^6^ conidia. Following 21–28 days of growth, half of the flasks were heat-treated at 80°C for 2 hours to produce the heat-inactivated particle control. The remaining flasks served as the viable test article. The heat-inactivated particle control and viable S. chartarum flasks were transferred to the National Institute for Occupational Safety and Health (NIOSH) inhalation facility and placed in a desiccator for 7–10 days prior to aerosolization.

### Quality Assurance

Quality assurance and quality control of heat-inactivated and viable S. chartarum consisted of testing cultures each week using internal transcribed spacer gene sequencing. This method allowed the amplification and detection of potentially contaminating mycobiota sources as described in ‎Appendix A. Cultures were also tested weekly to ensure reproducibility and production of nonviable S. chartarum. All identified fungal DNA belonged to S. chartarum with no contaminating fungi detected in the viable or heat-inactivated S. chartarum cultures. Heat inactivation resulted in an average of 98.63% reduction in S. chartarum (Table A-1).

## Test Article Generation and Exposure System

NIOSH has developed a computer-controlled acoustical generator system (AGS), in which acoustical energy is used to release the fungal spores into a nose-only exposure chamber. Figure 2 shows the AGS based on a modified acoustically powered particle (Pitt-3) generator, which was originally described by Weyel et al.^95^ The Pitt-3 generator was purchased from the University of Pittsburgh and evaluated under conditions recommended by its engineering school.^96^ The system was then fitted with a computer controller, further modified to its current design,^97,98^ and used by NIOSH to study the respiratory effects caused by the inhalation of a wide variety of occupationally relevant dusts. The AGS was initially used as a new and improved system for dispersing nanomaterials^99^ and was subsequently modified for fungal spore aerosolization as described by Buskirk et al.^100^ Fungi were grown on rice as described above, placed on the rubber membrane of the AGS, and aerosolized using acoustical energy. Inhalation of fungal spores simulates natural fungal exposures in the environment better than other routes of exposure. Several studies conducted by NIOSH to date using the AGS demonstrated that fungal aerosols can be reproducibly administered to mice housed in the nose-only exposure chamber,^27-29,100-102^ including a National Toxicology Program (NTP) study assessing the toxicological response to Aspergillus fumigatus.^30^

Figure 2

Illustration Showing the Acoustical Generator Nose-only Exposure System

TEM = transmission electron microscope; SEM = scanning electron microscope. High-efficiency particulate air-filtered supply air is directed into the acoustical generator, which vibrates at a designated frequency to form fungal spore aerosols from the fungus-coated rice grains. The fungal aerosol is directed into a nose-only chamber, and then the air is filtered before being sent into the exhaust system. A light-scattering instrument (DataRAM4; ThermoElectron Co., Franklin, MA) attached to the computer estimated the real-time aerosol mass concentration. This value was multiplied by a scale factor to determine the real-time number of spores deposited in the mouse lung based on the previously measured aerosol size distribution and a custom lung-deposition model. The software used that value to alter the amplitude of the speaker signal during exposures to obtain the desired chamber mass concentration.

Initial aerosolization studies demonstrated that the AGS produced an S. chartarum aerosol composed of single conidia of similar size (3–5 µm) and morphology in both the viable test article (S. chartarum) and heat-inactivated particle control groups (Figure 3). However, unlike the heat-inactivated particle control, a significant proportion of the viable S. chartarum aerosol was also composed of smaller fragments (<2 µm, Figure 3A).^28^

Figure 3

Aerodynamic Particle Size Measurements and Electron Microscopy Images Captured Following Aerosolization of Stachybotrys chartarum Conidia

Top panel images depict the size distribution of fungal particles measured with the aerodynamic particle sizer following aerosolization of (A) the test article, viable S. chartarum conidia, and (B) the heat-inactivated particle control, nonviable S. chartarum conidia. Bottom panel images display field emission scanning electron microscopy images of conidia collected on filters following acoustical generator system (AGS) aerosolization of (C) the test article conidia and (D) the heat-inactivated particle control. Images demonstrate that both groups result in an aerosol consisting of single conidia of similar size (3–5 µm), as well as the smaller fungal fragments seen only in the test article group.

Aerosolized viable S. chartarum and the heat-inactivated particle control were delivered to male and female B6C3F1/N mice housed in a multianimal nose-only exposure chamber via the AGS as previously described.^27,28^ Animals were exposed two times per week for 3 months via inhalation. In addition, an air control group received the same high-efficiency particulate air [filter] (HEPA)-filtered air that was being used to deliver viable S. chartarum.

Inhalation exposures were achieved by weighing and then placing the mice in a custom-built nose-only multianimal exposure carousel connected to the AGS as described in McKinney et al.^99^ Mice were placed in random pods for each exposure to minimize the effects of slight concentration differences observed within individual ports. Although the nose-only carousel houses up to 24 pods (Figure 2), only 20 pods (10 male and 10 female mice) were used during each exposure. Additional ports served as sample ports for the collection and analysis of test articles. The air control, heat-inactivated particle control, and viable S. chartarum-exposed animals were exposed using different chambers located in the same inhalation exposure room.

B6C3F1/N mice were exposed to viable S. chartarum or heat-inactivated particle control until the DataRAM software estimated that a total of approximately 1 × 10^4^ conidia had been deposited within the lungs during the 1-hour exposure session. Figure 4 shows the estimated pulmonary deposition following each exposure for the duration of the study. The estimation software used a mouse-lung-deposition model developed by the NIOSH Inhalation Facility, which was based on deposition measurements from Raabe et al.^103^ During viable S. chartarum or heat-inactivated particle control exposures, lung-deposition calculations were achieved using real-time DataRAM mass concentration measurements and a previously described scaling factor that estimated the number of conidia deposited in the lungs of mice in real time.^100,102^ The integrated value of mass deposition per unit time was calculated throughout the exposures. The AGS automatically turned off when the desired total conidia deposition had been delivered to the mice; however, the mice continued to receive HEPA-filtered humidified (approximately 40% relative humidity) air supplied at a flow rate of 6 L/min until 60 minutes had been reached. Each exposure corresponded to a 60-minute average mass concentration of approximately 8 mg/m^3^ (viable S. chartarum) or 7 mg/m^3^ (heat-inactivated particle control). Gravimetric filters were also collected during each exposure to continually monitor and adjust the DataRAM calibration. Air control mice received only HEPA-filtered air supplied to the chamber at the same flow rate (6 L/min) and time (60 minutes) as S. chartarum-exposed mice. All environmental conditions were kept constant in each carousel between control and test article animals.

Figure 4

Estimated Pulmonary Deposition of Stachybotrys chartarum Conidia for Each Exposure over the Course of the Three-month Study

Values represent the number of conidia estimated to deposit in the lung for viable S. chartarum (solid circles) and heat-inactivated particle control (open circles) exposure groups.

## Animal Source

Male and female B6C3F1/N mice (n = 20/exposure group and 20 sentinel mice) were obtained from the NTP colony maintained by Taconic Biosciences, Inc. (Germantown, NY).

## Animal Welfare

Animal care and use were in accordance with the Public Health Service Policy on Humane Care and Use of Animals. The NIOSH Inhalation Facility is an environmentally controlled barrier facility that is fully accredited by AAALAC International. Studies were approved by the CDC-Morgantown Animal Care and Use Committee and conducted in accordance with all NIOSH animal procedures and policies.

## Exposure Concentration Selection Rationale

An estimated pulmonary dose of 1 × 10^4^ S. chartarum conidia (viable or heat-inactivated conidia) was chosen for this study. This concentration was the highest aerosolized dose that reproducibly induced a lymphoproliferative response and was the same concentration and schedule used for a previously published pulmonary immunology study.^27,28^ This estimated lung burden would be equivalent to that of a worker breathing a constant workplace air concentration of 3.45 × 10^6^ conidia/m^3^ (146 μg/m^3^) for 1 week, working 8 hours per day for 5 days, and is comparable to an occupational exposure concentration of 10^3^–10^7^ conidia/m^3^, which has been reported to result in toxicosis.^43^

## Three-month Study

Mice were approximately 5 to 6 weeks old on receipt. The animals were weighed, distributed randomly into groups of approximately equal initial mean body weights, and randomly assigned to viable S. chartarum, heat-inactivated particle control, or air control groups. Mice were initially identified via tail marking, using a permanent marker and a consecutive numbering system.

Animals that weighed >10% or <10% of the mean of the group were placed in the sentinel group (n = 20). At 4 weeks and at study termination, serological analyses for bacterial and viral pathogens were performed on 10 male and 10 female sentinel mice using the protocol of the NIOSH Sentinel Animal Program (‎Appendix C).

Before the study, the mice were acclimated to the NIOSH animal facility for a minimum of 7 days. Afterward, to reduce potential stress from exposures, the mice were acclimated to the housing units used for the exposures (nose-only carousel) for 1 week (two 1-hour acclimations) before the initial fungal exposure. Study mice were placed individually in the carousel housing units (pods), and humidified HEPA-filtered air was supplied to the chamber for 1 hour on 2 separate days during the week before the initial exposures. After acclimation was complete and before the exposures began, the mice were tattooed using a consecutive numbering system.

Male and female B6C3F1/N mice were randomly assigned to viable S. chartarum, heat-inactivated particle control, and air control groups. Using a modified NTP protocol, groups of 10 male and 10 female mice were placed in individual pods on the carousel on the same 2 days of the week for 26 exposures (3 months). The mouse positions in the carousel were rotated throughout the study to account for any dose variability based on pod placement. Male and female mice were exposed for 1 hour per day to 8 mg/m^3^ (resulting lung dose = 1 × 10^4^) viable S. chartarum conidia, 7 mg/m^3^ (resulting lung dose = 1 × 10^4^) heat-inactivated S. chartarum conidia (particle control), or HEPA-filtered air (air control) that was delivered through the AGS into the nose-only exposure chamber at a flow rate of 6 L/min.

Following acclimation and exposures, the animals were transferred from the individual carousel housing pods to a standard cage environment located in an adjoining room within the facility. Male and female mice were housed in HEPA-filtered ventilated polycarbonate cages on autoclaved hardwood chip bedding. Male B6C3F1/N mice were individually housed during acclimation and the in-life phases of the study because of social incompatibilities, whereas female mice were housed in groups of five. Enrichment was provided to all cages and consisted of crinkle cut kraft paper. The room temperature of the animal facility was maintained between 68°F and 76°F, and the relative humidity ranged between 17% and 70% (Table 1). The light/dark cycle was maintained at 12-hour intervals. Mice were provided feed and tap water ad libitum, except when housed in the pods during acclimation or exposures. Sentinel mice selected during the acclimation period were housed within the same room and were free of viral and bacterial pathogens (Appendix C).

Table 1 Experimental Design and Materials and Methods for the Three-month Inhalation Study of Stachybotrys chartarum

Three-month Study
Study Laboratories
National Institute for Occupational Safety and Health (Morgantown, WV) Battelle (Columbus, OH)
Strain and Species
B6C3F1/N mice
Animal Source
Taconic Biosciences, Inc. (Germantown, NY)
Time Held before Studies
19 days
Average Age When Studies Began
8 weeks
Date of First Exposure
April 4, 2016
Duration of Exposure
3 months
Date of Last Exposure
June 29, 2016
Necropsy Date
June 30, 2016
Average Age at Necropsy
21 weeks
Size of Study Groups
10 males and 10 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights.
Animals per Cage
1 (male), 5 (females)
Method of Animal Identification
Tail tattoo
Diet
Irradiated NTP-2000 wafers (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed at least weekly
Water
Tap water (Morgantown, WV municipal supply) provided in water bottles ad libitum
Cages
HEPA-filtered, ventilated polycarbonate cages housed in a cage rack system (Lab Products Inc., Seaford, DE). Cages that housed three or more mice (females) were changed weekly. Cages that housed two or fewer mice (males) were changed every other week.
Bedding
Autoclaved hardwood chip bedding (Teklad Certified Sani-Chips^®^; Envigo, Madison, WI) and irradiated crinkle cut kraft paper were provided for nesting/enrichment (Crink-l’Nest^™^; The Andersons, Inc., Maumee, OH) and changed with cage changes.
Animal Room Environment
Temperature: 71.97°F± 1.41°F (min: 67.72°F, max: 75.78°F) Relative Humidity: 50.16% ± 11.82% (min: 17.10%, max: 69.27%) Room fluorescent light: 12 hours/day Room air changes: 10–15/hour
Test Article
Stachybotrys chartarum (S. chartarum, CASRN 67892-26-6) conidia: untreated (viable) or heat-inactivated particle controls Synonyms: Stachybotrys atra (S. atra); Stachybotrys alternans (S. alternans); Stachybotrys chartarum (Ehrenb.) S. Hughes 1958; anamorphic, satratoxin-producing chemotype (CBS 414.95; IBT 9460)
Exposure Concentrations
Estimated lung depositions: Air control: 0 (HEPA-filtered air only) Heat-inactivated particle control: 1 × 10^4^ nonviable S. chartarum conidia (exposure chamber mass concentration: ~7 mg/m^3^) Test article: 1 × 10^4^ viable S. chartarum conidia (exposure chamber mass concentration: ~8 mg/m^3^)
Type and Frequency of Observation
Observed once daily on nonexposure days (morning) and twice daily on exposure days (morning/afternoon). Clinical findings were recorded at each observation and at study termination. Animals were weighed initially and then weekly until study termination.
Method of Euthanasia
Intraperitoneal injection of a lethal dose of sodium pentobarbital (100–300 mg/kg; Fatal Plus, Vortech Pharmaceuticals, Dearborn, MI) followed by exsanguination via cardiac puncture.
Necropsy
Necropsies were performed on all study mice. Organs weighed were epididymides (left and right), heart, kidneys (left and right), liver, lungs, ovaries (left and right), testes (left and right), and thymus.
Hematology
Blood was collected from all surviving study mice via cardiac puncture at study termination. Hematological analyses included hematocrit, erythrocyte count, reticulocyte count, hemoglobin, mean cell volume, mean cell hemoglobin, mean cell hemoglobin concentration, platelet count, and leukocyte count and differential.
Histopathology
Complete histopathology was performed on all study mice. In addition to gross lesions, the following tissues were examined: adrenal gland, aorta, bone marrow, brain, esophagus, eye, femur, gallbladder, Harderian gland, heart, intestine (large and small), kidney, larynx, liver, lung, lymph nodes (bronchial, mandibular, mediastinal, mesenteric), mammary gland, nose, pancreas, pancreatic islets, parathyroid gland, pituitary gland, salivary glands, skin, spleen, stomach, thymus, thyroid gland, trachea, and urinary bladder. Other male tissues examined included the epididymis, preputial gland, prostate gland, seminal vesicle, and testes. Other female tissues examined included the cervix, clitoral gland, ovary, uterus, and vagina.

HEPA = high-efficiency particulate air.

Study animals were weighed upon initial receipt, and body weights were recorded weekly until study termination. Clinical observations were recorded daily for the duration of the study, once a day (morning) on nonexposure days and twice a day (morning/afternoon) on exposure days. Information about the study design, facilities, and animal maintenance is provided in Table 1. The report on feed composition and contaminants is provided in Appendix B.

## Clinical Examinations and Pathology

At the completion of the 3-month study, the mice were injected intraperitoneally with a lethal dose of sodium pentobarbital euthanasia solution (100–300 mg/kg). Peripheral blood for hematology and micronuclei determination was obtained via cardiac puncture. Whole blood (a minimum of 600 µL) was collected in tubes containing potassium ethylenediaminetetraacetic acid, and 400 µL were immediately processed for hematology using a ProCyte Dx hematology analyzer (IDEXX Laboratories, Inc., Westbrook, ME). Table 1 lists the parameters measured. A minimum of 200 µL of blood was immediately refrigerated and shipped to Integrated Laboratory Systems, LLC (ILS; Research Triangle Park, NC) for micronuclei determination.

Necropsies were performed at the NIOSH site by Battelle staff (Columbus, OH) in random order on all animals surviving to terminal sacrifice. The organs weighed at terminal necropsy included the left and right epididymides, heart, left and right kidneys, liver, lungs, left and right ovaries, left and right testes, and thymus. Bilateral organs were weighed and recorded separately. At necropsy, the tissues in Table 1 were examined in situ for gross lesions, removed, and then fixed and preserved in 10% neutral buffered formalin. Exceptions included the eyes and testes (epididymis and vaginal tunics of testes), which were initially fixed in Davidson’s solution and modified Davidson’s solution, respectively, then transferred to 10% neutral buffered formalin. The collected and fixed tissues were then shipped to the Battelle facility and further processed and trimmed, embedded in paraffin, sectioned at a thickness of 5 µm, and stained with hematoxylin and eosin (H&E). Histological sections of aorta, gallbladder, heart, liver, lung (all five lobes), bronchial lymph node, and spleen were stained with Grocott’s methenamine silver (GMS) stain for fungal elements. Battelle laboratory pathologists conducted a complete histopathological examination on all air control, heat-inactivated particle control, and viable S. chartarum-exposed mice. Table 1 lists the tissues and organs that were examined.

Microscopic evaluations were completed by a board-certified veterinary pathologist, and the pathology data were entered into the NTP Provantis software (Instem Stone, UK). The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory and storage. An audit of pathology specimens was conducted wherein the wet tissues, blocks, and slides were examined by technical staff for quality and adherence to NTP Specifications,^104^ and the wet tissues were examined by a team of pathologists to ensure all were sampled according to NTP Specifications. The slide and tissue counts were also verified. Slide-mounted, H&E-stained slides were evaluated by a team of quality assessment (QA) pathologists at a pathology laboratory independent of the study laboratory for accuracy and consistency of diagnoses. The histotechnique was also evaluated.

After a review of the laboratory reports and selected histopathology slides by a QA pathologist, the findings and reviewed slides were submitted to the Pathology Working Group (PWG) coordinator. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologist were resolved by the DTT pathology peer-review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, DTT pathologist, and QA pathologist/PWG coordinator. Details of these review procedures have been described, in part, by Boorman^105^ and Maronpot.^106^

## Statistical Methods

### Calculation and Analysis of Nonneoplastic Lesion Incidences

The incidences of nonneoplastic lesions are presented as numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. Fisher’s one-sided exact test,^107^ a procedure that uses the overall proportion of affected animals, was used to determine significance between all pairs of the three exposure groups.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of all pairwise comparisons between exposed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed using a one-way analysis of variance with post hoc Tukey Honest Significant Difference test^108^ for all pairwise comparisons among the three exposure groups. Hematology data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison method of Dunn.^109^ Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^110^ were examined by DTT personnel, and implausible values were eliminated from the analyses.

## Quality Management

The 3-month study was conducted in compliance with U.S. Food and Drug Administration Good Laboratory Practice Regulations whenever possible.^111^ To comply with the NIOSH Health Effects Laboratory Division (HELD) Laboratory Quality Management System, this study was conducted using validated standard operating procedures and performed in accordance with a CDC-Morgantown Animal Care and Use Committee-approved animal protocol, as well as a HELD Office of the Director-approved study protocol.^112^ In addition, gross pathology and histopathology study records were audited retrospectively by an independent QA contractor against study records submitted to the NTP Archives. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Toxicity Report. Audit procedures and findings are presented in the reports and are on file at the National Institute of Environmental Health Sciences. The audit findings were reviewed and assessed by DTT and NIOSH staff, and all comments were resolved or otherwise addressed during the preparation of this Toxicity Report.

## Genetic Toxicology

The genetic toxicity of S. chartarum was assessed by determining the frequency of micronucleated erythrocytes in mouse peripheral blood. The protocol for these studies and the results are given in Appendix D.

The genetic toxicity studies have evolved from an earlier effort to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the relationship between the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were developed originally to clarify proposed mechanisms of chemical-induced DNA damage, given the relationship between electrophilicity and mutagenicity,^113^ and the somatic mutation theory of cancer.^114,115^ Not all cancers, however, arise through genotoxic mechanisms.

### Peripheral Blood Micronucleus Test

Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division.^116,117^ Acute in vivo bone marrow chromosome aberration and micronucleus tests appear to be less predictive of carcinogenicity than the Salmonella test.^118,119^ However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies.^120^ Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is essential to the overall understanding of the risks associated with a particular exposure.