# Introduction

Figure 1

Stachybotrys chartarum (CASRN 67892-26-6)

Botanical name: Stachybotrys chartarum. Synonyms: Stachybotrys chartarum (S. chartarum); Stachybotrys atra (S. atra); Stachybotrys alternans (S. alternans); Stachybotrys chartarum (Ehrenb.) S. Hughes 1958; anamorphic, satratoxin-producing chemotype (CBS 414.95; IBT 9460).^a^ The light microscopic image depicts asexual S. chartarum reproductive structures composed of septate hyphae, conidiophores, and conidiospores.

a IBT 9460 is an anamorphic, satratoxin-producing S. chartarum chemotype (chemotype S) originally isolated from a water-damaged building in Finland.^1^

Image courtesy of Mold & Bacteria Consulting Laboratories.^2^

## Fungi, Indoor Environmental Quality, and Public Health

Fungi are a diverse kingdom with an estimated 5.1 million species.^3^ These eukaryotic organisms contain membrane-bound organelles with a rigid cell wall composed of mannose proteins, complex polysaccharides such as α/β glucans, chitin, and ergosterol.^4,5^ The lifecycles of fungi can be unicellular yeast, multicellular hyphae, or a combination of the two (dimorphism). Fungi reproduce asexually or sexually and produce spores, which can also be produced by a variety of other organisms including plants and bacteria. Conidia are asexual fungal spores that are morphologically distinct, ranging from 2 to >120 µm in size.^4^ Fungi are mostly saprophytic heterotrophs that obtain nutrients from decaying organic material, allowing growth in environments ranging from soil, agricultural commodities, and indoor environments containing cellulose-based building material. Although most fungal species are not pathogenic, some cause disease in plants, animals, and humans, and the potential for adverse health effects following fungal exposure has become an area of public concern in the United States.

Damp indoor environments may provide optimal growth conditions required for fungal proliferation. Abiotic or biotic disturbances can result in the aerosolization of fungal bioaerosols composed of spores, filamentous hyphae, or microscopic fragments into the surrounding environment. Exposure can also occur in occupational settings, including forestry, agriculture, service, and manufacturing, and can consist of spore concentrations exceeding 10^8^ colony-forming units per cubic meter (CFU/m^3^).^6^ Along with spores, hyphal fragments can also be aerosolized into the breathing zone of exposed individuals and can be found at higher concentrations than spores.^7-12^ Fungal bioaerosols can contain secondary microbial metabolites, such as mycotoxins and microbial volatile organic compounds (MVOCs), that have the potential to further exacerbate the negative health responses following exposure.

A study of water-damaged building materials collected from damp indoor environments (n = 72) identified fungal genera including Penicillium (68%), Aspergillus (56%), Chaetomium (22%), Ulocladium (21%), Stachybotrys (19%), and Cladosporium (15%), all of which are known to cause respiratory allergy.^13^ Of these six commonly identified fungi, Stachybotrys chartarum was one of the most frequently detected fungal species. In 1994, evidence of acute idiopathic pulmonary hemosiderosis (IPH) was identified in infants residing in Cleveland, OH.^14,15^ Further investigation suggested that more of the infants diagnosed with acute IPH resided in water-damaged homes than in homes that did not contain water damage, and S. chartarum was identified as a potential causative agent.^15^ However, a later report published by the Centers for Disease Control and Prevention refuted those results, stating that the evidence presented in the initial report did not support the epidemiological associations between water damage, S. chartarum exposure, and acute IPH.^15^ Although the initial association between human illness and mold contamination was nullified, awareness of the association between fungal exposure and human health was already heightened.

Following the Cleveland investigation, consensus documents from the Institute of Medicine, Committee on Damp Indoor Spaces and Health,^16^ and the World Health Organization^17^ identified epidemiological evidence of associations between exposure to mold contamination in damp indoor environments and adverse respiratory symptoms such as asthma, dyspnea, wheeze, cough, respiratory infections, bronchitis, allergic rhinitis, eczema, and upper respiratory tract symptoms.^18^ In addition, fungal exposure has been associated with allergic bronchopulmonary mycoses and hypersensitivity pneumonitis.^6,19^ In 2017, cost estimate analyses indicated that the direct health-care costs of all fungal-related diseases exceeded $7.2 billion, which included $4.5 billion from hospitalizations and $2.6 billion from outpatient visits.^20^ Although associations between mold contamination in damp indoor environments and adverse health effects have been identified, the pulmonary and systemic toxicity resulting from repeated fungal exposure remains largely unknown. In addition, there are no current exposure limits or regulations in place to protect individuals who encounter contaminated fungal environments.

To address these knowledge gaps, fungi were nominated to the National Toxicology Program (NTP) in May 2004. The NTP Board of Scientific Counselors and Executive Committee suggested studying fungal species commonly identified in indoor environments, including Aspergillus, Alternaria, and Stachybotrys. In 2007, an expert review panel discussed the NTP subchronic study design, including the fungal test article production, characterization, and reproducibility of the test article generation. As a participant of the review panel, the National Institute for Occupational Safety and Health (NIOSH) was identified as a collaborative partner to conduct subchronic (13-week) inhalation studies to examine the toxicological effects following repeated fungal exposure. To complete these subchronic inhalation exposures, NIOSH developed a computer-controlled acoustical generator system (AGS) to deliver dry aerosolized fungal test articles to mice housed in nose-only chambers to model a natural human inhalation exposure that would occur in residential or occupational environments. The use of the AGS circumvents limitations of other administration methods, including intranasal exposure,^21^ intratracheal instillation,^22-25^ and liquid aerosol inhalation.^26^ Environmentally and occupationally relevant fungal species nominated to NTP have been independently tested in both pilot immunology studies conducted by NIOSH^27-29^ and in toxicology studies reported by NTP in collaboration with NIOSH.^30^

A 4-week and 13-week pilot exposure study using the AGS evaluated the pulmonary immune responses to repeated S. chartarum exposure.^27^ Following the initial optimization and characterization of the S. chartarum test articles, including a heat-inactivated biological particle control,^28^ groups of B6C3F1/N female mice repeatedly inhaled one of two viable trichothecene-producing strains of S. chartarum twice a week for a total of 4 or 13 weeks.^27^ The two S. chartarum strains used in the pilot study were IBT 9460 and IBT 7711. IBT 9460 is a macrocyclic trichothecene-producing strain that produced a higher level of mycotoxin and fragmented to a greater extent than IBT 7711.^28^ Separate groups of mice inhaled either nonviable S. chartarum conidia (a heat-inactivated particle control for each respective strain) or high-efficiency particulate air [filter] (HEPA)-filtered air only. Pulmonary arterial remodeling, characterized by airway inflammation with a granulocyte infiltration, was observed after 4 weeks of S. chartarum IBT 9460 exposure. Granulocyte infiltration switched to more of a lymphocytic and macrophage infiltration after 13 weeks of exposure to both IBT 9460 and IBT 7711. Perivascular inflammation and bronchiolar epithelial cell hyperplasia were also observed. Flow cytometry analysis of bronchoalveolar lavage fluid (BALF) from exposed mice showed an increase in eosinophils, neutrophils, and macrophages following a 13-week exposure to both IBT 9460 and IBT 7711. However, the progression of cellular infiltrates and immunopathological responses progressed more rapidly in IBT 9460-exposed mice compared to IBT 7711-exposed mice, suggesting that the presence of fungal fragments plays a critical role in the pulmonary immune response to S. chartarum exposure.

In an NTP study conducted in collaboration with NIOSH describing the toxicological responses following a subchronic A. fumigatus exposure, the incidence of nonneoplastic lesions was significantly increased in the larynx, lung, and bronchial lymph nodes of viable A. fumigatus-exposed male and female B6C3F1/N mice compared to the control groups.^30^ In the lung, arterial medial hypertrophy was identified and described as circumferential thickening of the tunica media of small and medium arterioles and arteries by concentric layers of hypertrophied and hyperplastic smooth muscle cells. In addition, chronic-active inflammation, defined as the increased presence of neutrophils, was observed in the lung tissue following subchronic exposure to A. fumigatus. Bronchus-associated lymphoid tissue (BALT) hyperplasia and goblet cell metaplasia were also observed following A. fumigatus exposure. Squamous metaplasia of the epiglottis was observed in the larynx of both male and female mice exposed to viable A. fumigatus compared to the heat-inactivated particle control and air control groups. Evaluation of the bronchial lymph nodes showed significantly increased incidences of lymphocyte hyperplasia and plasma cell hyperplasia relative to either the heat-inactivated particle control or air control groups.^30^

The purpose of these studies on A. fumigatus was to characterize the toxicological and pulmonary immunological responses following repeated exposure to fungal contaminants commonly identified in occupational and damp indoor environments. Using a method that replicates a more natural human exposure has provided unique opportunities to define the mechanisms by which these fungal species cause adverse respiratory health effects. To further understand the hazards following S. chartarum exposure, NIOSH employed this same methodology to characterize the toxicological responses following subchronic exposure to S. chartarum strain IBT 9460, a high trichothecene-producing, high fragmenting strain of S. chartarum.

## Chemical and Physical Properties

The genus Stachybotrys is an asexually reproducing, filamentous fungal genus that includes 50 species found worldwide and belongs to the Ascomycota order Hypocreales, family Stachybotryaceae.^31^ S. chartarum is a macroscopic saprophyte that is greenish black in color, leading to the common name “black mold.” This fungus was first identified in 1818 as Stillbospora chartarum Ehrenb.^32^ In 1837, August Carl Joseph Corda identified the fungus as Stachybotrys atra following collection from wallpaper in a house in Prague,^33^ which was then reclassified as S. chartarum (Ehrenb.) S. Hughes 1958.^34^ S. chartarum requires a cellulose-rich substrate, such as drywall, wallpaper, gypsum board, or cardboard, and high moisture content for optimal growth.^35-37^ S. chartarum can grow at a range of temperatures, but the most optimal condition for growth is 30°C at 93%–94% humidity.^38^ Frazer and colleagues^39^ showed different temperature and water activities are required for the germination and growth of S. chartarum compared to sporulation. S. chartarum is often found in damp indoor environments.^1,11,40-42^ Consequently, one study comparing water-damaged building materials collected from damp indoor environments (n = 72) identified S. chartarum more often than other fungal species such as Penicillium chrysogenum and A. versicolor.^13^

The mycelium of S. chartarum is characterized by the formation of dark, slimy masses of conidia (spores) that sporulate abundantly from phialides. The phialides are 9–14 mm in length and often occur in whorls that extend from the tip of conidiophores connected to septate hyphae. S. chartarum conidia are smooth or ridged, ellipsoid, and unicellular and range from 7 to 12 µm in length and 4 to 6 µm in width.^43^ The aerodynamic diameter of aerosolized S. chartarum (strain IBT 9460) conidia has been reported to be approximately 3–5 µm^28^; however, one study showed that North American strains have an average aerodynamic diameter of 5.6 µm, but the conidia size was variable, and approximately one-third of the conidia tested were within the respiratory range.^43^ This high variability in conidia size could potentially be due to the presence of fungal fragments, a notion supported by aerosolization studies describing the high occurrence of fungal fragments. One study conducted by Lemons et al. used S. chartarum strain IBT 9460 and showed that acoustical generation resulted in the aerosolization of not only intact S. chartarum conidia (3–5 µm) but also of fungal fragments (<2 µm aerodynamic diameter) derived from conidia, phialides, and hyphae that initially constituted 50% of the total fungal particle count.^28^ Cho et al. conducted a separate study, which found that S. chartarum fungal fragments were aerosolized at concentrations 514 times higher than S. chartarum spores.^8^

It has been suggested that the mycotoxins produced by S. chartarum contribute to the adverse health effects observed following exposure.^22,37,44-46^ Two chemotypes of S. chartarum exist, chemotype S and chemotype A, and are defined by the mycotoxins produced. Used for this current study, chemotype S produces toxic macrocyclic trichothecenes including satratoxins, roridins, and verrucarins,^47,48^ whereas chemotype A produces less toxic atranones.^1,49^ In addition, S. chartarum also produces phenylspirodrimanes,^41^ trichoverrols,^50^ trichoverrins,^50^ and spirocyclic drimanes,^1^ as well as MVOCs,^51^ which individuals could encounter within S. chartarum-contaminated environments.

## Human Exposure

S. chartarum is distributed worldwide and is found in soil and on cellulose-rich materials including hay, straw, plant debris, and building materials.^35,37,52^ Human exposure to contaminated materials, such as straw contaminated with S. chartarum, has resulted in dermatological and adverse respiratory health effects.^53,54^ Exposure to S. chartarum can occur via dermal contact, ingestion, and inhalation; however, studies have shown that exposure occurs primarily through direct skin contact and inhalation.^44,54^ S. chartarum spores do not readily disperse into the air because of the slime droplet encasing the phialides but can become aerosolized when the fungus dries and is disturbed via biotic or abiotic air movements.^44^ Exposure to fungal bioaerosols, which include S. chartarum, generated from disturbances within fungal-contaminated, water-damaged environments have been associated with poor indoor air quality^11,48^ and adverse respiratory health effects.^16,17^

Fungal bioaerosols can be composed of spores, filamentous hyphae, and microscopic fragments. Fungal fragments have the potential to aerosolize at higher concentrations than spores.^7-12^ In addition, certain strains of S. chartarum fragment to a greater extent compared to other S. chartarum strains or fungal species^11,28^ and may contribute to the adverse respiratory outcomes following S. chartarum exposure.^27^ Case reports have identified an association between indoor S. chartarum exposures and respiratory symptoms,^55-57^ immunological dysfunction,^58^ and neurological disease; however, there is a lack of evidence for neurotoxicity.^41^

S. chartarum has been detected in water-damaged environments such as schools, offices, and home dwellings^13,58-61^ and has been associated with “sick building syndrome” and damp-related building illness.^44,46,59,62-66^ Workers remediating S. chartarum-contaminated material from buildings reported symptoms, including throat irritation, fatigue, muscle aches, and skin rashes.^57^ Sampling of contaminated work areas resulted in an estimated air concentration of 2 × 10^4^ CFU/m^3,58,67^ which coincided with other measured S. chartarum airborne levels reported to be 7 × 10^5^ viable conidia/m^3^.^43^ A case control study of 10 infants with pulmonary hemorrhage from Cleveland, OH reported the mean air concentration of S. atra (synonym S. chartarum) was 43 CFU/m^3^ compared to 4 CFU/m^3^ in the homes of infants without pulmonary hemorrhage.^68^ Residents living in water-damaged homes have shown severe asthma with an allergic reaction to Stachybotrys antigens isolated from moldy carpets.^69^ Neurological and flu-like symptoms, fatigue, dermatitis, and malaise have also been reported from a home with identified Stachybotrys contamination, symptoms of which resolved following the removal of Stachybotrys-contaminated material.^55^ Several studies that have characterized the responses of individuals exposed to S. chartarum suggested that the symptoms reported were likely caused by inhalation of the fungal toxins.^56,58,61^

S. chartarum is considered nonpathogenic.^70^ The ability of the species to contribute to adverse health outcomes is suggested to be caused by the allergenicity, inflammatory response, or toxicity of S. chartarum. It was once thought that S. chartarum was incapable of infection because of the lack of physical evidence of the organism within a symptomatic individual. Most recently, however, Stachybotrys (S. chlorohalonata) was identified in the sinus tissues of a severely immunocompromised 23-year-old man.^71^ Although mycotoxins were also reported to contribute to the hemorrhaging observed in the immunocompromised male patient, this was the first report of an invasive case of Stachybotrys.

## Regulatory Status

Currently, there are no established guidelines for acceptable Stachybotrys concentrations in residential or occupational environments. In addition, no exposure limits have been proposed by any regulatory or governmental body.

## Toxicity

S. chartarum has been characterized as a toxigenic mold that can cause animal and human mycotoxicosis.^41^ The effect of S. chartarum trichothecenes was identified in the 1930s Russian equine outbreak when horses died after consuming S. chartarum-contaminated straw and grain.^52^ This newly found disease caused by ingesting or handling contaminated feed was termed stachybotryotoxicosis and has been reported worldwide in animals and humans.^43,53,72^ Farm workers exposed to S. chartarum-contaminated hay complained of dyspnea, airway obstruction, conjunctivitis, sore throat, mucosal irritation, and skin inflammation.^73^ Previous studies suggest that the occupational exposure concentrations resulting in trichothecene toxicosis were on the order of 10^3^–10^7^ conidia/m^3^.^43^ Although these mycotoxicosis cases were due to direct skin contact or ingestion, inhaling mycotoxins is considered more harmful because of the greater fungal bioavailability.^43^

Distinct mycotoxin profiles are produced by S. chartarum when grown on different culture media.^74^ However, research has indicated that the water activity (a_w_) must reach a level of 0.95 a_w_ before mycotoxins are produced.^48^ S. chartarum produces macrocyclic trichothecenes, such as satratoxins and isosatratoxins F, G, and H, roridin E and L-2, and verrucarins J and B. These macrocyclic trichothecenes are suggested to contribute in part to the adverse health effects following S. chartarum exposure.^22,37,44-48^ Research has shown that S. chartarum macrocyclic trichothecenes within indoor contaminated environments can become airborne and are associated with both conidia^75^ and fungal fragments.^76,77^ Mycotoxins have been associated with particle sizes ≥3 µm, which correspond to conidia; however, trichothecene mycotoxins, such as satratoxin H and verrucarin J, have been shown to be associated with other S. chartarum components, including submicron fragments that can be inhaled and deposited deep within the lung.^78^

In general, satratoxins have been reported to be produced in larger amounts compared to the other trichothecenes.^72^ In mice, the median lethal dose (LD_50_) for satratoxin has been reported to be approximately 1 mg/kg.^79^ Following the aerosolization of S. atra (syn. S. chartarum) conidia, Sorenson et al. confirmed the presence of satratoxin H within the bioaerosol, as well as satratoxin G and trichoverrols A and B to a lesser extent.^80^ Satratoxin G has been reported to be the most cytotoxic of the satratoxins and five other trichothecenes studied.^81^ A single dose of ≥25 µg/kg satratoxin G administered via intranasal instillation resulted in neurotoxicity and inflammation within the nose and brain of female C57Bl/6 mice.^82^ Isosatratoxin F exposure altered the phospholipid synthesis, composition, and secretion of pulmonary surfactant in BALF in mice^83^ and resulted in cytological alterations within fetal rabbit alveolar type II cells, indicative of cellular damage and apoptosis. Additionally, satratoxin-positive S. chartarum, as well as the trichothecene mycotoxins (roridin A, verrucarin A, and T-2 toxin), have been shown to induce apoptosis and inflammation in human primary macrophages.^84^

Stachylysin, a hemolysin released from S. chartarum,^85-87^ was thought to contribute to the infant pulmonary hemosiderosis cases reported in Cleveland, OH.^14,15,88^ To investigate this potential contribution, a study conducted by Vesper and Vesper^88^ measured the production of stachylysin from the S. chartarum strains isolated from infant pulmonary hemosiderosis case houses in Cleveland, OH^46^ and in an isolate from the lung of a pulmonary hemosiderosis patient in Texas.^89^ Results showed the isolated S. chartarum strains produced stachylysin, suggesting a potential role in the reported pulmonary hemosiderosis cases.^88^

Exposure to atranones A and C has also been shown to result in immunotoxic and inflammatory responses in the lungs of male Swiss Webster (CFW) mice following a single dose of ≥2 µg/animal via intratracheal instillation.^90^ Rand et al. suggested that different atranones exhibit varying levels of inflammation with different toxicokinetics.^90^ Another study showed that a single exposure to a nontoxin-producing strain of S. chartarum could induce airway irritation and elicit an immune response in male Swiss Webster (CFW) mice.^26^

Fungi also produce MVOCs, and similar to mycotoxins, the production of MVOCs depends on the growth media. For example, MVOCs unique to S. chartarum include 1-butanol, 3-methyl-2-butanol, 3-methyl-1-butanol, and thujopsene and have been detected on rice inoculated with S. chartarum, while 1-butanol was detected on inoculated gypsum board.^51^ MVOCs emitted from contaminated fungal environments have additionally been implicated in central nervous system symptoms such as headaches, inability to concentrate, or dizziness.^91^

Research surrounding the toxic effect of exposure to spores, secondary metabolites, or MVOCs of S. chartarum has been confounding. It has been predicted that the adverse health effects observed in animal models are caused by exposure to high spore or mycotoxin concentrations that exceed those encountered in even the most heavily contaminated environments.^37,92^ However, the pediatric IPH cases identified in Cleveland, OH^15^ occurred after exposure to fungal-contaminated environments, suggesting that the spore or mycotoxin concentrations encountered in these damp indoor environments were sufficient to cause adverse health effects in children. Additionally, the length of fungal growth and substrate availability influenced the secondary metabolite profiles and the associated effect on adverse respiratory health effects.^93^ Regardless of the variability in toxin production, the results of most toxicological studies demonstrate that S. chartarum produces highly toxic trichothecenes that have been shown to contribute to adverse health effects.

## Reproductive and Developmental Toxicity

While not well studied, one report found that CFW male and female mice orally exposed to a single, low dose (3,000–4,000 tissue culture units) of S. alternans (syn. S. chartarum) prepared from grain or liquid medium infected with toxicogenic and nontoxicogenic strains resulted in a decreased number of pregnancies compared to control mice.^94^ In addition, mice from that same study that had ingested 100–4,000 tissue culture units of toxin had a significant increase in the frequency of dead, resorbed, or stunted fetuses compared to controls.

## Carcinogenicity

Several studies have evaluated the carcinogenicity of individual mycotoxins; however, no studies evaluating carcinogenicity following S. chartarum exposure were identified.

## Genetic Toxicity

Although studies evaluating the effect of purified mycotoxin exposure on genotoxicity exist, no studies evaluating the genetic toxicity following S. chartarum exposure were identified.

## Study Rationale

Following the nomination of fungi to NTP for comprehensive toxicity evaluation, NTP partnered with NIOSH to begin a series of studies to characterize the toxicological responses following exposure to NTP-nominated fungal species. The first of the series examined the toxicological responses to A. fumigatus^30^ following delivery of dry aerosolized fungal test articles twice a day for 13 weeks to male and female B6C3F1/N mice housed in nose-only chambers. The design of this inhalation study was to simulate a more natural exposure similar to what would be encountered in a water-damaged built environment. In this second inhalation toxicity study, S. chartarum was selected as the test article because of the heightened awareness of adverse health effects of fungal exposures encountered within indoor water-damaged environments. Although pulmonary immunological endpoints have been evaluated in pilot studies, the toxicological responses to S. chartarum exposure have not been fully characterized.