# Acknowledgments

The NIOSH co-authorship team would like to personally thank the NIOSH Inhalation Facility staff for weighing the animals and conducting the inhalation exposures of test article, heat-inactivated biological particle control, and air control groups. The NIOSH co-authorship team would also like to thank the NIOSH animal facility staff for ordering animals and diet, daily clinical observations, and overseeing the sentinel mice housing and testing program. This study was supported by internal NIOSH funds and in part by an interagency agreement between NIOSH and the National Institute of Environmental Health Sciences as a collaborative National Toxicology Program research activity (AES12007001-1-0-6-NIOSH reference 12-NS12-01).

This work was supported by the Intramural Research Program (ES103374, ES103376, ES103377, and ES103380) at the National Institute of Environmental Health Sciences, National Institutes of Health and performed for the National Toxicology Program, Public Health Service, U.S. Department of Health and Human Services under contracts HHSN273201800006C, GS00Q14OADU417 (Order No. HHSN273201600015U), HHSN273201600011C, HHSN273201600020C, HHSN273201500006C, HHSN273201500013C, HHSN273201300009C, HHSN273201300004C, HHSN316201200054W, and N01-ES-55536.