# Appendix E Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NTP-DATA-TOX-107.^121^

## E.1 Three-month Stachybotrys chartarum Study Tables - Mice

### E.1.1 Data Tables

I01 - Animal Removal Summary

I02 - Animal Removals

I03 - Growth Curve

I03C - Growth Curve

I04 - Mean Body Weight Summary

I04G - Mean Body Weight Gain Summary

I05 - Clinical Observations Summary

PA02 - Neoplastic Lesion Summary with Percent Incidence

PA03 - Nonneoplastic Lesion Summary with Percent Incidence

PA05 - Incidence Rates of Neoplastic Lesions with Systemic Lesions Abridged

PA06 - Organ Weights Summary

PA10X - Statistical Analysis of Nonneoplastic Lesions

PA14 - Individual Animal Pathology Data

PA18 - Incidence Rates of Nonneoplastic Lesions by Anatomic Site with Average Severity Grade

PA43 - Hematology Summary

PA46 - Summary of Gross Pathology

### E.1.2 Individual Animal Data

Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Gross Pathology Data

Individual Animal Hematology Data

Individual Animal Histopathology Data

Individual Animal Organ Weight Data

Individual Animal Removal Reasons Data

## E.2 Genetic Toxicology

### E.2.1 Stachybotrys chartarum (67892-26-6) in Micronucleus Study G04052 in Male B6C3F1/N Mice

G04 - In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data