# Appendix D Genetic Toxicology

## D.1 Evaluation Protocol

National Toxicology Program (NTP) reports consider biological as well as statistical factors to determine an overall assay result. For an individual assay, the statistical procedures for data analysis are described in the following protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. In such cases, all the data are critically evaluated with attention given to possible protocol variations in determining the weight of evidence for an overall conclusion of chemical activity in an assay. For in vitro assays conducted with and without exogenous metabolic activation, results obtained in the absence of activation are analyzed separately from results obtained in the presence of activation. The summary table in the abstract of this Toxicity Report presents the scientific judgment of the Division of Translational Toxicology (DTT) and the National Institute for Occupational Safety and Health (NIOSH) regarding the overall evidence for activity of the chemical in an assay.

## D.2 Micronucleus Assay

### D.2.1 Peripheral Blood Micronucleus Test Protocol

Peripheral blood samples were analyzed by Integrated Laboratory Systems, LLC (ILS; Research Triangle Park, NC) for determination of erythrocyte micronucleus frequencies. Briefly, ethylenediaminetetraacetic acid (EDTA)-stabilized peripheral blood samples were shipped on ice packs immediately following terminal necropsy from NIOSH to ILS. Before ILS received the samples, microcentrifuge tubes containing anticoagulant (heparin) were prepared and stored at 4°C, and 15 mL conical tubes containing fixative (methanol) were prepared and stored at −80°C ± 5°C.

Upon arrival, blood samples were fixed in ultracold methanol using a MicroFlowPLUS Kit (Litron Laboratories, Rochester, NY) according to the manufacturer’s instructions. Fixed samples were stored in a −80°C freezer until analysis. Thawed blood samples were analyzed for frequency of micronucleated immature erythrocytes (polychromatic erythrocytes or PCEs, reticulocytes) and mature erythrocytes (normochromatic erythrocytes or NCEs) using a flow cytometer^135^; both the mature and immature erythrocyte populations can be analyzed separately by employing special cell surface markers to differentiate the two cell types. In mice, both the mature and immature erythrocyte populations can be evaluated for micronucleus frequency because the mouse spleen does not sequester and eliminate damaged erythrocytes. Damaged erythrocytes achieve steady state in the peripheral blood of mice following 4 weeks of continuous exposure. Approximately 20,000 reticulocytes and 1 × 10^6^ erythrocytes were analyzed per animal for the frequency of micronucleated cells, and the percentage of immature erythrocytes (% PCE) was calculated as a measure of bone marrow toxicity resulting from test article exposure.

For most NTP studies, the statistical methods for micronucleus assays employ a trend test followed by Dunn pairwise tests. Due to the design of this study (with one exposed group and two control groups), no trend test is needed, and the Dunn test was used for the three-way pairwise comparison of the control and exposed groups. The Dunn test has a built-in correction for multiple comparisons so the overall false positive rate of the experiment can be maintained. Pairwise comparisons with the control groups are considered statistically significant at p ≤ 0.05.

Historical control data are used to evaluate the biological importance of any observed response. Both statistical significance and biological importance are considered when arriving at a call. The results of statistical analyses, reproducibility of any effects observed, and the magnitudes of those effects are all considered when determining the final call.

### D.2.2 Results

No significant increases in the frequencies of micronucleated reticulocytes and mature erythrocytes were observed in the peripheral blood of male or female B6C3F1/N mice exposed to either viable S. chartarum or heat-inactivated particle control conidia relative to the air control mice (Table D-1). Similarly, no significant increase in frequency was observed in mice exposed to viable S. chartarum conidia compared to mice exposed to the heat-inactivated particle control. In addition, no significant alteration in the percentage of reticulocytes was observed in these mice, suggesting no effects on hematopoiesis. These negative results in the micronucleus test indicate an absence of exposure-induced chromosomal damage in progenitor erythrocytes in the bone marrow of mice, along with an absence of generalized bone marrow toxicity.

Table D-1. Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male and Female Mice in the Three-month Inhalation Study of Stachybotrys chartarum

| Number of Mice with Erythrocytes Scored | MN-RET/1,000^a^ | P Value^b^ | MN-ME/1,000^a^ | P Value^b^ | % RET^a^ | P Value^b^
Male
Air Control | 5 | 3.120 ± 0.12 | | 1.636 ± 0.04 | | 1.844 ± 0.06
Heat-inactivated Particle Control | 5 | 3.200 ± 0.37 | 1.000 | 1.672 ± 0.05 | 1.000 | 1.769 ± 0.09 | 0.688
Viable S. chartarum^c^ | 5 | 3.040 ± 0.12 | 1.000/1.000 | 1.618 ± 0.08 | 1.000/0.688 | 1.764 ± 0.08 | 1.000/1.000
Female
Air Control | 5 | 1.820 ± 0.15 | | 1.027 ± 0.03 | | 1.900 ± 0.10
Heat-inactivated Particle Control | 5 | 2.120 ± 0.18 | 0.384 | 1.084 ± 0.04 | 0.867 | 2.031 ± 0.07 | 1.000
Viable S. chartarum^c^ | 5 | 1.960 ± 0.11 | 1.000/1.000 | 1.004 ± 0.05 | 1.000/0.609 | 1.954 ± 0.21 | 1.000/1.000

MN-RET = micronucleated reticulocytes; MN-ME = micronucleated mature erythrocytes; RET = reticulocytes.

^a^ Data are presented as mean ± standard error.

^b^ Pairwise comparisons with the air or heat-inactivated particle control groups were performed by the Dunn test.

^c^ P values for the viable S. chartarum groups are presented as: p value (viable S. chartarum compared to air control)/p value (viable S. chartarum compared to heat-inactivated particle control).