# Appendix B Ingredients, Nutrient Composition, and Contaminant Levels in NTP-2000 Mouse Ration

Table B-1. Ingredients of NTP-2000 Mouse Ration

Ingredients | Percent by Weight
Ground Hard Winter Wheat | 23.00
Ground #2 Yellow Shelled Corn | 22.44
Wheat Middlings | 15.0
Oat Hulls | 8.5
Alfalfa Meal (Dehydrated, 17% Protein) | 7.5
Purified Cellulose | 5.5
Soybean Meal (49% Protein) | 4.0
Fish Meal (60% Protein) | 4.0
Corn Oil (without Preservatives) | 3.0
Soy Oil (without Preservatives) | 3.0
Dried Brewer’s Yeast | 1.0
Calcium Carbonate (USP) | 0.9
Vitamin Premix^a^ | 0.5
Mineral Premix^b^ | 0.5
Calcium Phosphate, Dibasic (USP) | 0.4
Sodium Chloride | 0.3
Choline Chloride (70% Choline) | 0.26
Methionine | 0.2

USP = United States Pharmacopeia.

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table B-2. Vitamins and Minerals in NTP-2000 Mouse Ration

| Amount^a^ | Source
Vitamins
Vitamin A | 4,000 IU | Stabilized vitamin A palmitate or acetate
Vitamin D | 1,000 IU | D-activated animal sterol
Vitamin K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl Acetate | 100 IU | –
Niacin | 23 mg | –
Folic Acid | 1.1 mg | –
α-Pantothenic Acid | 10 mg | α-Calcium pantothenate
Riboflavin | 3.3 mg | –
Thiamine | 4 mg | Thiamine mononitrate
B_12_ | 52 µg | –
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | d-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

^a^ Per kg of finished diet.

Table B-3. Nutrient Composition of NTP-2000 Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 14.3 | – | 1
Crude Fat (% by Weight) | 7.9 | – | 1
Crude Fiber (% by Weight) | 9.49 | – | 1
Ash (% by Weight) | 5.05 | – | 1
Amino Acids (% of Total Diet)
Arginine | 0.808 ± 0.073 | 0.67–0.97 | 31
Cystine | 0.220 ± 0.021 | 0.15–0.25 | 31
Glycine | 0.703 ± 0.037 | 0.62–0.8 | 31
Histidine | 0.341 ± 0.068 | 0.27–0.68 | 31
Isoleucine | 0.548 ± 0.039 | 0.43–0.66 | 31
Leucine | 1.096 ± 0.061 | 0.96–1.24 | 31
Lysine | 0.070 ± 0.101 | 0.31–0.86 | 31
Methionine | 0.409 ± 0.040 | 0.26–0.49 | 31
Phenylalanine | 0.623 ± 0.045 | 0.471–0.72 | 31
Threonine | 0.513 ± 0.040 | 0.43–0.61 | 31
Tryptophan | 0.156 ± 0.026 | 0.11–0.2 | 31
Tyrosine | 0.425 ± 0.064 | 0.28–0.54 | 31
Valine | 0.666 ± 0.038 | 0.55–0.73 | 31
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.936 ± 0.229 | 3.49–4.55 | 31
Linolenic | 0.304 ± 0.030 | 0.21–0.368 | 31
Vitamins
Vitamin A (IU/kg) | 3,270 | – | 1
α-Tocopherol (ppm) | 2,376 ± 12,602 | 13.6–69,100 | 30
Thiamine (ppm)^b^ | 7.4 | – | 1
Riboflavin (ppm) | 8.32 ± 2.868 | 4.2–17.5 | 31
Niacin (ppm) | 79.78 ± 8.978 | 66.4–98.2 | 31
Pantothenic Acid (ppm) | 26.28 ± 10.69 | 17.4–81.0 | 31
Pyridoxine (ppm)^b^ | 9.832 ± 2.080 | 6.44–14.3 | 31
Folic Acid (ppm) | 1.61 ± 0.434 | 1.15–3.27 | 31
Biotin (ppm) | 0.319 ± 0.113 | 0.0–0.704 | 31
B_12_ (ppb) | 48.82 ± 33.79 | 18.3–174.0 | 31
Choline (as Chloride) (ppm) | 2,553 ± 632 | 1,160–3,790 | 31
Minerals
Calcium (%) | 0.943 | – | 1
Phosphorus (%) | 0.573 | – | 1
Potassium (%) | 0.663 ± 0.035 | 0.563–0.733 | 31
Chloride (%) | 0.389 ± 0.044 | 0.3–0.517 | 31
Sodium (%) | 0.194 ± 0.027 | 0.153–0.283 | 31
Magnesium (%) | 0.216 ± 0.052 | 0.185–0.49 | 31
Iron (ppm) | 190.0 ± 35.69 | 135–311 | 31
Manganese (ppm) | 49.87 ± 9.15 | 21.0–73.1 | 31
Zinc (ppm) | 56.53 ± 24.87 | 42.5–184 | 31
Copper (ppm) | 7.64 ± 2.42 | 3.21–16.3 | 31
Iodine (ppm) | 0.50 ± 0.232 | 0–0.972 | 31
Chromium (ppm) | 1.164 ± 1.16 | 0.33–3.97 | 30
Cobalt (ppm) | 0.217 ± 0.148 | 0.086–0.864 | 29

^a^ From formulation.

^b^ As hydrochloride.

Table B-4. Contaminant Levels in NTP-2000 Mouse Ration

| Mean | Number of Samples
Contaminants
Arsenic (ppm) | 0.252 | 1
Cadmium (ppm) | 0.051 | 1
Lead (ppm) | 0.066 | 1
Mercury (ppm) | 0.01 | 1
Selenium (ppm) | 0.145 | 1
Aflatoxins (ppb)^a^ | <5.0 | 1
Nitrate Nitrogen (ppm)^b^ | 11.5 | 1
Nitrite Nitrogen (ppm)^a,b^ | <0.12 | 1
BHA (ppm)^a,c^ | <1.0 | 1
BHT (ppm)^a,c^ | <1.0 | 1
Aerobic Plate Count (CFU/g)^a^ | <10.0 | 1
Coliform (MPN/g)^a^ | <3 | 1
Escherichia coli (MPN/g)^a^ | <10 | 1
Salmonella sp. (MPN/g) | Negative | 1
Total Nitrosamines (ppb)^d^ | 9.1 | 1
N-Nitrosodimethylamine (ppb)^d^ | 5.0 | 1
N-Nitrosopyrrolidine (ppb)^d^ | 4.1 | 1
Pesticides (ppm)
α-BHC^a^ | <0.01 | 1
β-BHC^a^ | <0.02 | 1
γ-BHC^a^ | <0.01 | 1
δ-BHC^a^ | <0.01 | 1
Heptachlor^a^ | <0.01 | 1
Aldrin^a^ | <0.01 | 1
Heptachlor Epoxide^a^ | <0.01 | 1
DDE^a^ | <0.01 | 1
DDD^a^ | <0.01 | 1
DDT^a^ | <0.01 | 1
HCB^a^ | <0.01 | 1
Mirex^a^ | <0.01 | 1
Methoxychlor^a^ | <0.05 | 1
Dieldrin^a^ | <0.01 | 1
Endrin^a^ | <0.01 | 1
Telodrin^a^ | <0.01 | 1
Chlordane^a^ | <0.05 | 1
Toxaphene^a^ | <0.01 | 1
Estimated PCBs^a^ | <0.20 | 1
Ronnel^a^ | <0.01 | 1
Ethion^a^ | <0.02 | 1
Trithion^a^ | <0.05 | 1
Diazinon^a^ | <0.10 | 1
Methyl Chlorpyrifos | 0.19 | 1
Ethyl Chlorpyrifos | <0.025 | 1
Methyl Pirimiphos | <0.02 | 1
Methyl Parathion^a^ | <0.025 | 1
Ethyl Parathion^a^ | <0.02 | 1
Malathion^a^ | <0.02 | 1
Endosulfan I^a^ | <0.02 | 1
Endosulfan II | 0.12 | 1
Endosulfane Sulfate^a^ | <0.01 | 1

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.