# Appendix A Culture, Characterization, and Delivery of Stachybotrys chartarum

## A.1 Reconstitution, Culture, and Glycerol Stock Preparation of Stachybotrys chartarum

The Stachybotrys chartarum strain (CBS 414.95, IBT 9460) used in this study was originally isolated from a water-damaged building in Finland. Malt extract agar (MEA) culture plates were aseptically inoculated with 20 µL of the stored glycerol stock in a class II biological safety cabinet (BSC). MEA culture plates were incubated at 26°C for 10–14 days for optimal spore growth. S. chartarum conidia (spores) were harvested by liberating the conidia in 2 mL of sterile water using an inoculating loop. The conidia suspension was mixed with an equal volume of 50% glycerol, and 0.5-mL aliquots of the suspension were prepared in cryogenic storage vials. Glycerol stock preparations were stored at −80°C for the duration of the study.

## A.2 Preparation of the Viable Stachybotrys chartarum Test Article

One aliquoted frozen glycerol conidia stock was thawed, and two MEA culture plates were aseptically inoculated with 20 µL of the stock suspension in a BSC. Plates were incubated at 26°C for 12–14 days. S. chartarum conidia were harvested from each plate by liberating the conidia in 2 mL of sterile water (W3500, Sigma Aldrich, St. Louis, MO) using an inoculating loop. The concentration of the conidia suspension was determined by diluting the suspension 1:100, and conidia counts were determined using a hemocytometer. The conidia suspension was diluted to 2.5 × 10^5^ conidia/mL using sterile water. Mahatma-enriched extra-long grain white rice (30 g) and distilled deionized water (10 mL) were added to twelve 250-mL flasks covered with aluminum foil, autoclaved at 121°C for 30 minutes, and allowed to cool in a BSC. Once cooled, these 12 flasks were aseptically inoculated with 5 mL of the 2.5 × 10^5^ conidia/mL suspension, recapped with foil, and incubated at 26°C for 21–28 days. The flasks were shaken vigorously one time after 1 week of growth to prevent aggregation of the rice grains. At the end of the growth phase, the foil caps were punctured using aseptic technique and the flasks were laid horizontally in a biological safety cabinet to increase the surface area during the drying phase. Cultures were placed in a desiccator for 7–10 days for drying prior to aerosolization. Preparation of the viable test article for the first week of exposures was initiated 1 month before the start of the 3-month exposure period.

## A.3 Preparation of Stachybotrys chartarum Heat-inactivated Particle Control

After 21–28 days of culture, 6 of the 12 fungi-coated rice culture flasks were immersed in a dry bead bath (Lab Armor, Irving, TX) set to 80°C for 2 hours and allowed to cool. As with the viable test articles, the heat-inactivated particle control flasks were then placed in a desiccator for 7–10 days before aerosolization.

## A.4 Determination of the Reduction in Stachybotrys chartarum Conidia Viability in the Heat-inactivated Particle Control

S. chartarum conidia were harvested from heat-inactivated particle control cultures every other week by removing 10–20 random conidia-laden rice grains from the cultures and placing them in a 15-mL tube containing 5 mL sterile water. Conidia suspensions were diluted to 1 × 10^5^ conidia/mL, and 100 µL were plated on MEA culture plates (1 × 10^4^ conidia/plate). After 48–96 hours of growth at 25°C, fungal colony-forming units (CFU) were counted to determine the number of viable S. chartarum conidia/mL. The percentage of viable conidia in the heat-inactivated particle control was then calculated. The cultures were categorized as nonviable if >95% of the conidia were not viable.

## A.5 Assessment of Fungal Contaminants in the Exposure Articles

Genomic DNA was extracted from the heat-inactivated particle control and viable S. chartarum cultures every other week to analyze fungal contaminants using the Roche High Pure PCR Template Preparation Kit (Roche, Indianapolis, IN). Conidia were harvested from 10–20 conidia-laden rice grains in sterile distilled, deionized water. Conidia from 200 µL of the suspension were pelleted by centrifugation and suspended in Roche Tissue Lysis Buffer (200 µL) containing 5 µL of CelLytic B Cell Lysis Reagent (Sigma Aldrich, St. Louis, MO); tubes were incubated at 37°C for 30 minutes. Next, 200 µL Roche Binding Buffer and 40 µL proteinase K solution was added, and tubes were incubated at 70°C for 10 minutes. After the addition of 100 µL of isopropanol, extracted DNA was washed and eluted according to the manufacturer’s recommendations. Internal transcribed spacer (ITS) regions of fungal ribosomal RNA were amplified using the Fun18Sf/ITS4R primer pair, and purified amplicons were cloned into a pDRIVE vector that was then transformed into chemically competent Escherichia coli. E. coli clones positive for the ITS amplicon insert were used to inoculate 96-well plates for the generation of glycerol stocks. The glycerol stocks were sequenced with the T7 and SP6 primers using Sanger sequencing. Forward and reverse sequences were trimmed and assembled and then clustered into operational taxonomic units (groups of sequences with ≥97% similarity). Representative sequences from each operational taxonomic unit were searched against sequences deposited in the National Center for Biotechnology Information database and identified based on sequence identity. Any sequences identified as a fungal species other than S. chartarum or Stachybotrys spp. were considered fungal contaminants. The number of sequences analyzed was dependent on the number of viable conidia in the sample. Very low DNA yield from heat-inactivated particle control samples was a result of heat treatment. The number of contaminant fungal sequences is shown relative to the number of sequences analyzed in each sample in Table A-1.

## A.6 Aerosolization of the Exposure Articles Using the Acoustical Generator System

Prior to aerosolization of the exposure test articles, the viable S. chartarum and heat-inactivated particle control cultures were placed in a desiccator for 7–10 days to remove excess moisture and allow optimal aerosolization. Fungal-laden rice was placed on a rubber membrane housed on top of a speaker within the acoustical generator system (AGS), a modified Pitt-3 generator^95^ linked to a multianimal nose-only exposure chamber. The Pitt-3 generator was purchased from the University of Pittsburgh and evaluated under conditions recommended by its engineering school.^96^ The exposure chamber consisted of a vertical cylindrical tower with 24 ports (4 levels of 6 ports) holding animal pods that projected outward radially (Figure 2). The system was fitted with a computer controller, further modified to its current design,^97,98^ and used by the National Institute for Occupational Safety and Health (NIOSH) to study the respiratory effects caused by the inhalation of a wide variety of occupationally relevant dusts. The AGS was initially used as a new and improved system for dispersing nanomaterials^99^ and was subsequently modified for fungal spore aerosolization as described by Buskirk et al.^100^ Two AGS systems were used in this study: one for the viable S. chartarum exposures and one for the heat-inactivated particle control exposures. Air control mice were placed in an identical exposure chamber that was not attached to the AGS but received the same high-efficiency particulate air [filter] (HEPA)-filtered air delivered to the test article chamber. Twenty animal pods were attached to each exposure chamber, 10 for male mice and 10 for female mice. Animals were randomly placed in the pods for each exposure to minimize the effects of potential minor variations in conidia concentrations at each port. The additional ports served as sample ports to collect mass concentration, particle size, and samples on filters for field emission electron microscopy analysis (Hitachi S-4800, Tokyo, Japan).

The fungal-laden rice was allowed to settle within the AGS before the start of exposure. Acoustical energy was then used to aerosolize fungal conidia, which were delivered into the exposure chamber at a flow rate of 6 L/min. Particle size and mass concentration data were needed to estimate the total lung particle deposition during each exposure. Three pods were reserved as sample ports. The first port was used to gravimetrically measure the mass concentration, and the second used a light-scattering device (DataRAM4, ThermoElectron Co., Franklin, MA) to provide real-time estimates of the mass concentration (Con) during exposures. The gravimetric filter data were used to validate and calibrate the DataRAM4 every exposure. The third sample pod was used to collect aerodynamic particle size data (APS, TSI Inc., Soreview, MN). The APS data were collected the week before the start of animal exposures. To collect these data, the system was run in an identical manner as an animal exposure without animals present, and when the real-time mass concentration reading was stable, several 2-minute APS samples were taken. The average DataRam4 readings during the 2-minute APS samples were noted (Con_DuringAPS).

An estimate of the total number of particles deposited in the upper and lower airways was calculated each second (TPDs) by the custom Labview software during each exposure run, using the following equation:

T P D s = S x C o n

Wherein:

S = deposition scale factor, particle number/(mg/m^3^)

Con = real-time DataRam4 concentration, mg/m^3^

The deposition scale factor (S), used in the above equation, was calculated before the beginning of animal exposures with the following equation:

S = (M V x ∑_i = 1_^i = 52^ {N c o n ( i ) x (D F _ A l v e o l a r (i) + D F _ T r a c h e o (i))})/(( C o n _ D u r i n g A P S x 60 s e c . ))

Wherein:

MV = estimated animal breathing minute volume, set to 25 for the current study, mL

i = midpoint of each of the 52 APS aerodynamic size classification channels, ranging from 0.5 to 20 µm

Ncon(i) = the number concentration of particles that fall within the smallest bin size range

DF_Alveolar(i) = mouse lung alveolar deposition fraction for particle size i, ranging from 0 to 1^b^

b The mouse-lung-deposition model was based on interpolated data from Raabe et al.103. Raabe OG, Al-Bayati MA, Teague SV, Rasolt A. Regional deposition of inhaled monodisperse coarse and fine aerosol particles in small laboratory animals. Ann Occup Hyg. 1988; 32 Suppl 1(Inhaled Particles VI):53-63. https://doi.org/10.1093/annhyg/32.inhaled_particles_VI.53

DF_Tracheo(i) = mouse lung tracheobronchial deposition fraction for particle size i, ranging from 0 to 1^b^

Con_DuringAPS = average mass concentration during the APS measurement, mg/m^3^

The custom Labview software would keep a running total of particles deposited, and when the estimate reached the target daily dose, the particle generator would shut off and deliver HEPA-filtered air to the exposure chamber for the remainder of the 60-minute exposure interval. If the estimated particles deposited did not reach the target within 1 hour, the exposure was stopped, and the estimated count of particles deposited was noted. For the current study, the estimated pulmonary deposition was 1 × 10^4^ conidia, equating to approximately 7 mg/m^3^ heat-inactivated conidia and 8 mg/m^3^ viable fungal conidia.

Table A-2 and Table A-3 describe the measured exposure concentrations of each exposure. APS data are shown in Table A-4. The columns represent the three different methods of producing size distribution curves (as seen in Figure 3). The aerodynamic particle sizer totals the particles in each particle size by number, by the surface area of the particles in each size bin, and by the mass of the particles in each size bin. Field emission electron microscopy analysis showed that the aerosol primarily consisted of single conidia within the 3–5 µm range (Figure 3).

Table A-1. Weekly Evaluation of Viable Stachybotrys chartarum and Heat-inactivated Particle Control

| Heat-inactivated Particle Control | Viable S. chartarum
Viability ^a^
Viable Spore Concentration | 1.37 × 10^3^ conidia/mL (±1.62 × 10^3^) | ND
Percentage Nonviable | 98.63% (±1.62%) | –
Contamination ^b^
Week 1 | 0/0^c^ | 0/76
Week 3 | 0/40 | 0/42
Week 5 | 0/39 | 0/93
Week 7 | 0/0^c^ | 0/0^c^
Week 9 | 0/43 | 0/92
Week 11 | 0/0^c^ | 0/85
Week 13 | 0/0^c^ | 0/88

ND = not determined.

^a^ Data are presented as mean (± standard deviation).

^b^ DNA derived from S. chartarum was the only fungal DNA detected in heat-inactivated particle control and test article cultures. Heat inactivation destroyed the DNA in heat-inactivated particle controls most weeks and resulted in fewer or no fungal sequences to analyze compared to viable test articles.

^c^ Limited genomic DNA yield did not allow for completion of sequence analysis.

Table A-2. Weekly Viable Stachybotrys chartarum Exposure Concentrations

Exposure Day | Chamber Concentration (DataRAM [mg/m^3^]) | Chamber Concentration (Filter [mg/m^3^]) | Filter Weight (mg) | Number of Conidia Deposited in Lung
1 | 8.16 | 8.34 | 0.501 | 1.011 × 10^4^
3 | 8.13 | 7.32 | 0.440 | 1.009 × 10^4^
8 | 7.96 | 6.01 | 0.370 | 1.010 × 10^4^
10 | 8.01 | 7.85 | 0.480 | 1.009 × 10^4^
15 | 8.10 | 8.54 | 0.512 | 1.008 × 10^4^
17 | 7.97 | 7.56 | 0.454 | 1.009 × 10^4^
22 | 8.06 | 8.10 | 0.490 | 1.008 × 10^4^
24 | 8.03 | 8.20 | 0.500 | 1.008 × 10^4^
30 | 7.66 | 8.28 | 0.530 | 1.013 × 10^4^
32 | 8.02 | 10.82 | 0.660 | 1.009 × 10^4^
36 | 8.12 | 8.49 | 0.510 | 1.008 × 10^4^
38 | 8.16 | 8.53 | 0.510 | 1.009 × 10^4^
43 | 7.84 | 8.74 | 0.540 | 1.011 × 10^4^
45 | 7.94 | 8.02 | 0.497 | 1.010 × 10^4^
50 | 8.11 | 9.09 | 0.545 | 1.007 × 10^4^
52 | 8.12 | 10.57 | 0.630 | 1.009 × 10^4^
58 | 7.62 | 7.58 | 0.485 | 1.008 × 10^4^
60 | 8.00 | 10.02 | 0.611 | 1.013 × 10^4^
64 | 7.77 | 9.44 | 0.595 | 1.005 × 10^4^
66 | 8.10 | 6.87 | 0.412 | 1.009 × 10^4^
71 | 7.97 | 9.21 | 0.562 | 1.008 × 10^4^
73 | 8.04 | 8.58 | 0.523 | 1.007 × 10^4^
78 | 7.50 | 6.90 | 0.449 | 1.009 × 10^4^
80 | 7.91 | 9.56 | 0.593 | 1.007 × 10^4^
85 | 8.10 | 9.34 | 0.560 | 1.008 × 10^4^
87 | 8.01 | 8.97 | 0.547 | 1.009 × 10^4^
Mean^a^ | 7.98 ± 0.17 | 8.50 ± 1.12 | 0.520 ± 0.067 | 1.009 × 10^4^ ± 17.51

^a^ Data are presented as mean ± standard deviation of the measurement over the course of the study.

Table A-3. Weekly Heat-inactivated Particle Control Exposure Concentrations

Exposure Day | Chamber Concentration (DataRAM [mg/m^3^]) | Chamber Concentration (Filter [mg/m^3^]) | Filter Weight (mg) | Number of Conidia Deposited in Lung
1 | 7.08 | 6.56 | 0.390 | 1.019 × 10^4^
3 | 7.10 | 7.54 | 0.450 | 1.023 × 10^4^
8 | 7.06 | 9.81 | 0.590 | 1.016 × 10^4^
10 | 7.05 | 8.06 | 0.480 | 1.020 × 10^4^
15 | 7.13 | 8.66 | 0.515 | 1.028 × 10^4^
17 | 7.07 | 6.40 | 0.384 | 1.032 × 10^4^
22 | 7.14 | 9.25 | 0.560 | 1.029 × 10^4^
24 | 7.15 | 8.70 | 0.520 | 1.027 × 10^4^
30 | 7.14 | 9.37 | 0.570 | 1.029 × 10^4^
32 | 7.08 | 8.83 | 0.530 | 1.017 × 10^4^
36 | 6.80 | 9.59 | 0.590 | 1.011 × 10^4^
38 | 6.99 | 9.55 | 0.570 | 1.008 × 10^4^
43 | 7.27 | 9.48 | 0.570 | 1.049 × 10^4^
45 | 6.96 | 9.77 | 0.596 | 1.019 × 10^4^
50 | 7.04 | 4.89 | 0.293 | 1.014 × 10^4^
52 | 7.07 | 6.02 | 0.360 | 1.018 × 10^4^
58 | 6.94 | 5.78 | 0.353 | 1.021 × 10^4^
60 | 7.08 | 5.62 | 0.337 | 1.026 × 10^4^
64 | 7.12 | 7.39 | 0.444 | 1.028 × 10^4^
66 | 7.10 | 7.10 | NA | 1.026 × 10^4^
71 | 7.15 | 9.07 | 0.544 | 1.029 × 10^4^
73 | 7.11 | 8.26 | 0.496 | 1.023 × 10^4^
78 | 6.79 | 6.04 | 0.374 | 1.017 × 10^4^
80 | 7.08 | 8.64 | 0.518 | 1.018 × 10^4^
85 | 7.03 | 8.06 | 0.491 | 1.029 × 10^4^
87 | 6.99 | 9.41 | 0.574 | 1.028 × 10^4^
Mean^a^ | 7.06 ± 0.10 | 7.99 ± 1.50 | 0.484 ± 0.092 | 1.023 × 10^4^ ± 81.84

NA = not available.

^a^ Data are presented as mean ± standard deviation of the measurement over the course of the study.

Table A-4. Aerodynamic Particle Size Statistics of Aerosolized Stachybotrys chartarum Based on Aerodynamic Particle Sizer Measurements

| Number (Particle Size) | Surface (Particle Size) | Mass (Particle Size)
Viable S. chartarum
Median (µm) | 2.88 ± 0.12 | 4.26 ± 0.03 | 4.43 ± 0.03
Mean (µm) | 2.75 ± 0.05 | 4.14 ± 0.03 | 4.43 ± 0.03
Geometric Mean (µm) | 2.22 ± 0.05 | 3.95 ± 0.03 | 4.30 ± 0.02
Mode (µm) | 4.27 ± 0.17 | 4.37 ± 0.00 | 4.37 ± 0.00
Geometric Standard Deviation | 2.02 ± 0.01 | 1.41 ± 0.01 | 1.29 ± 0.01
Heat-inactivated Particle Control
Median (µm) | 3.77 ± 0.17 | 4.10 ± 0.11 | 4.26 ± 0.11
Mean (µm) | 3.77 ± 0.22 | 4.21 ± 0.16 | 4.44 ± 0.20
Geometric Mean (µm) | 3.63 ± 0.26 | 4.10 ± 0.16 | 4.32 ± 0.17
Mode (µm) | 3.84 ± 0.11 | 4.02 ± 0.11 | 4.12 ± 0.12
Geometric Standard Deviation | 1.34 ± 0.07 | 1.25 ± 0.03 | 1.25 ± 0.03

Values represent the average ± standard deviation of aerodynamic particle sizer measurements taken in 2-minute durations for the test article (n = 3) and heat-inactivated particle control (n = 6).