# Overview

The potential adverse effects of various vanadium compounds were previously assessed in National Toxicology Program (NTP) studies. Vanadium pentoxide is commercially produced and imported for use as an industrial intermediate in the production of vanadium and steel alloys as well as for other industrial purposes. Concern about human exposure to vanadium pentoxide is primarily in the occupational setting via inhalation. The results of NTP toxicity and carcinogenicity studies in F344/N rats and B6C3F1 mice following whole-body inhalation exposure to vanadium pentoxide for 16 days, 3 months, or 2 years were previously published.^1^ A 28-day immunotoxicity study of sodium metavanadate in B6C3F1/N mice exposed via drinking water was also conducted as part of the NTP vanadium research program. Potential human oral exposure to vanadium compounds is likely due to its presence in food and drinking water from natural and anthropogenic sources and the use of vanadium-containing dietary supplements. Vanadium in food and drinking water can be found in various oxidation states with the most prevalent being tetravalent (V^4+^) and pentavalent (V^5+^). Vanadyl sulfate and sodium metavanadate were selected as representative tetravalent and pentavalent vanadium compounds, respectively, to assess the potential toxicity of vanadium oral exposure. To select exposure concentrations for the current studies, 14-day drinking water studies of vanadyl sulfate and sodium metavanadate were performed and are published.^2,3^