# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8992

DOI: https://doi.org/10.22427/NTP-TOX-106

Report Series: NTP Toxicity Report Series

Report Series Number: 106

Official citation: National Toxicology Program (NTP). 2023. NTP technical report on the toxicity studies of sodium metavanadate (CASRN 13718-26-8) and vanadyl sulfate (CASRN 27774-13-6) administered in drinking water to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats and B6C3F1/N mice. Research Triangle Park, NC: National Toxicology Program. Toxicity Report 106.