# Peer Review

The National Toxicology Program (NTP) conducted a peer review of the draft NTP Technical Report on the Toxicity Studies of Sodium Metavanadate (CASRN 13718-26-8) and Vanadyl Sulfate (CASRN 27774-13-6) Administered in Drinking Water to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats and B6C3F1/N Mice by letter in November 2022 by the experts listed below. Reviewer selection and document review followed established NTP practices. The reviewers were charged to:

1. Peer review the draft NTP Technical Report on the Toxicity Studies of Sodium Metavanadate and Vanadyl Sulfate Administered in Drinking Water to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats and B6C3F1/N Mice.
2. Comment on NTP’s interpretations of the data.

NTP carefully considered reviewer comments in finalizing this report.

## Peer Reviewers

- Rebecca Fry, Ph.D.
  Carol Remmer Angle Distinguished Professor and Associate Chair, Department of Environmental Sciences and Engineering
  University of North Carolina at Chapel Hill
  Chapel Hill, North Carolina, USA
- Norman Barlow, Ph.D.
  Vice President, Preclinical Sciences
  Xencor
  Monrovia, California, USA