# Collaborators

- Division of Translational Toxicology, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Designed studies, evaluated and interpreted results, and reported findings
  G.K. Roberts, Ph.D., Study Scientist
  M.F. Cesta, D.V.M., Ph.D., Study Pathologist
  C.R. Blystone, Ph.D.
  M.C. Cora, D.V.M.
  H.C. Cunny, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  D.E. Malarkey, D.V.M., Ph.D. (Retired)
  B.S. McIntyre, Ph.D.
  E. Mutlu, Ph.D.
  V.G. Robinson, M.S.
  K.A. Shipkowski, Ph.D.
  K.R. Shockley, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S. (Retired)
- Provided oversight for data management
  J.M. Fostel, Ph.D.
- Battelle, Columbus, Ohio, USA
  Conducted studies and evaluated pathology findings
  M.R. Hejtmancik, Ph.D., Principal Investigator
  B.R. Sparrow, Ph.D., Principal Investigator
  K.E. Elsass, B.S.
  D.M. Fallacara, Ph.D.
  S.J. Harbo, D.V.M.
  K.A.B. Knostman, D.V.M., Ph.D.
  E. Mylchreest, Ph.D.
  A.J. Skowronek, D.V.M., Ph.D.
- Conducted prestart chemistry activities and dose formulations
  B.L. Burback, Ph.D., Principal Investigator
  S.W. Graves, B.S., Principal Investigator
  K.A. Carrico, B.A.
  M.A. Cloud, B.S.
  T.A. Cristy, B.A.
  R.E. Haney, M.S.
  J.S. Richey, M.S.
  B. Stiffler, Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Provided pathology review
  K.Y. Cimon, D.V.M., M.S. (Sodium Metavanadate)
  T.A. Crabbs, D.V.M. (Vanadyl Sulfate)
- Coordinated pathology data review
  E.M. Quist, D.V.M., Ph.D. (Vanadyl Sulfate)
  D. Tokarz, D.V.M., Ph.D. (Sodium Metavanadate)
- Coordinated Pathology Working Group on 3-month vanadyl sulfate studies (December 14, 2020)
  T.A. Crabbs, D.V.M.
- Coordinated Pathology Working Group on 3-month sodium metavanadate studies (December 17, 2020)
  K.Y. Cimon, D.V.M., M.S.
- ICF, Reston, Virginia, USA
  Contributed to technical writing and data integration and ensured report quality
  L.M. Prince, Ph.D.