# References

1 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of vanadium pentoxide (CAS No. 1314-62-1) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2002. NTP Technical Report No. 507. NIH Publication No. 03-4441. https://ntp.niehs.nih.gov/go/tr507abs
2 Roberts GK, Stout MD, Sayers B, Fallacara DM, Hejtmancik MR, Waidyanatha S, Hooth MJ. 14-day toxicity studies of tetravalent and pentavalent vanadium compounds in Harlan Sprague Dawley rats and B6C3F1/N mice via drinking water exposure. Toxicol Rep. 2016; 3:531–538. 10.1016/j.toxrep.2016.05.001 28042531
3 Roberts GK, Stout MD, Sayers B, Fallacara DM, Hejtmancik MR, Waidyanatha S, Hooth MJ. Clarification and lessons learned for reporting studies with hydrates. Citation: Roberts et al., 2016. Toxicology Reports 3: 531–538. Toxicol Rep. 2018; 5:207–208. 10.1016/j.toxrep.2017.12.023 29854590
4 National Center for Biotechnology Information (NCBI). PubChem Compound Summary for CID 34007, Vanadyl sulfate. Bethesda, MD: U.S. National Library of Medicine, National Center for Biotechnology Information; 2022. https://pubchem.ncbi.nlm.nih.gov/compound/34007
5 U.S. Environmental Protection Agency (USEPA). CompTox Chemicals Dashboard: Sodium metavanadate 13718-26-8 | DTXSID3044336. Washington, DC: U.S. Environmental Protection Agency; 2022. https://comptox.epa.gov/dashboard/chemical/details/DTXSID3044336
6 National Center for Biotechnology Information (NCBI). PubChem Compound Summary for CID 4148882, Sodium metavanadate. Bethesda, MD: U.S. National Library of Medicine, National Center for Biotechnology Information; 2022. https://pubchem.ncbi.nlm.nih.gov/compound/4148882
7 Rydzynski K, Pakulska D. Vanadium, niobium, and tantalum. In: Bingham E, Cohrssen B, editors. Patty’s Toxicology. 6th ed. Hoboken, NJ: John Wiley & Sons; 2012. p. 511–564. 10.1002/0471435139.tox037.pub2
8 Agency for Toxic Substances and Disease Registry (ATSDR). Toxicological profile for vanadium. Atlanta, GA: U.S. Department of Health and Human Services, Public Health Service, Agency for Toxic Substances and Disease Registry; 2012. https://www.atsdr.cdc.gov/toxprofiles/tp58.pdf
9 Pennington JAT, Jones JW. Molybdenum, nickel, cobalt, vanadium, and strontium in total diets. J Am Diet Assoc. 1987; 87(12):1644–1650. 10.1016/S0002-8223(21)03381-2 3680822
10 Sepe A, Ciaralli L, Ciprotti M, Giordano R, Funari E, Costantini S. Determination of cadmium, chromium, lead and vanadium in six fish species from the Adriatic Sea. Food Addit Contam. 2003; 20(6):543–552. 10.1080/0265203031000069797 12881127
11 Office of Dietary Supplements (ODS). Dietary Supplement Label Database (DSLD). Bethesda, MD: National Institutes of Health, Office of Dietary Supplements; 2022. https://dsld.od.nih.gov/
12 Kothandan S, Sheela A. DNA interaction and cytotoxic studies on mono/di-oxo and peroxo- vanadium (V) complexes - A review. Mini Rev Med Chem. 2021; 21(14):1909–1924. 10.2174/1389557521666210308143522 33687880
13 Adachi A, Asai K, Koyama Y, Matsumoto Y, Okano T. Subacute vanadium toxicity in rats. J Health Sci. 2000; 46(6):503–508. 10.1248/jhs.46.503
14 Ścibior A, Zaporowska H, Ostrowski J. Selected haematological and biochemical parameters of blood in rats after subchronic administration of vanadium and/or magnesium in drinking water. Arch Environ Contam Toxicol. 2006; 51(2):287–295. 10.1007/s00244-005-0126-4 16783625
15 Domingo JL, Paternain JL, Llobet JM, Corbella J. Effects of vanadium on reproduction, gestation, parturition and lactation in rats upon oral administration. Life Sci. 1986; 39(9):819–824. 10.1016/0024-3205(86)90460-1 3747732
16 Elfant M, Keen CL. Sodium vanadate toxicity in adult and developing rats: Role of peroxidative damage. Biol Trace Elem Res. 1987; 14(3):193–208. 10.1007/BF02795686 24254821
17 Poggioli R, Arletti R, Bertolini A, Frigeri C, Benelli A. Behavioral and developmental outcomes of prenatal and postnatal vanadium exposure in the rat. Pharmacol Res. 2001; 43(4):341–347. 10.1006/phrs.2000.0788 11352539
18 Boscolo P, Carmignani M, Volpe AR, Felaco M, Del Rosso G, Porcelli G, Giuliano G. Renal toxicity and arterial hypertension in rats chronically exposed to vanadate. Occup Environ Med. 1994; 51(7):500–503. 10.1136/oem.51.7.500 8044251
19 Carmignani M, Boscolo P, Volpe AR, Togna G, Masciocco L, Preziosi P. Cardiovascular system and kidney as specific targets of chronic exposure to vanadate in the rat: Functional and morphological findings. In: Chambers PL, Chambers CM, Wiezorek WD, Golbs S, editors. Recent Developments in Toxicology: Trends, Methods and Problems. Berlin, Germany: Springer-Verlag; 1991. p. 124–127. 10.1007/978-3-642-74936-0_24
20 Carmignani M, Volpe AR, Porcelli G, Boscolo P, Preziosi P. Chronic exposure to vanadate as factor of arterial hypertension in the rat: Toxicodynamic mechanisms. In: Bolt HM, de Wolff FA, Henderson PT, editors. Medical Toxicology: Proceedings of the 1991 EUROTOX Congress Meeting Held in Masstricht, September 1–4, 1991. Berlin, Germany: Springer-Verlag; 1992. p. 117–120. 10.1007/978-3-642-77260-3_15
21 Akgün-Dar K, Bolkent S, Yanardag R, Tunalı S. Vanadyl sulfate protects against streptozotocin-induced morphological and biochemical changes in rat aorta. Cell Biochem Funct. 2007; 25(6):603–609. 10.1002/cbf.1354 16892454
22 Sanchez DJ, Colomina MT, Domingo JL. Effects of vanadium on activity and learning in rats. Physiol Behav. 1998; 63(3):345–350. 10.1016/S0031-9384(97)00433-2 9469725
23 Sanchez DJ, Colomina MT, Domingo JL, Corbella J. Prevention by sodium 4,5-dihydroxybenzene1,3-disulfonate (tiron) of vanadium-induced behavioral toxicity in rats. Biol Trace Elem Res. 1999; 69(3):249–259. 10.1007/BF02783877 10468162
24 U.S. Environmental Protection Agency (USEPA). Drinking water Contaminant Candidate List (CCL) and regulatory determination. Washington, DC: U.S. Environmental Protection Agency; 2021. https://www.epa.gov/ccl
25 U.S. Environmental Protection Agency (USEPA). Contaminant Candidate List 1 - CCL 1. Washington, DC: U.S. Environmental Protection Agency; 2022. https://www.epa.gov/ccl/contaminant-candidate-list-1-ccl-1
26 U.S. Environmental Protection Agency (USEPA). IRIS assessment plan for oral exposure to vanadium and compounds (scoping and problem formulation materials). Washington, DC: U.S. Environmental Protection Agency, Office of Research and Development, Center for Public Health and Environmental Assessment, Integrated Risk Information System; 2020. EPA Report No. EPA/635/R-20/112. https://nepis.epa.gov/Exe/ZyPURL.cgi?Dockey=P1010XZ0.txt
27 Treviño S, Díaz A, Sánchez-Lara E, Sanchez-Gaytan BL, Perez-Aguilar JM, González-Vergara E. Vanadium in biological action: Chemical, pharmacological aspects, and metabolic implications in diabetes mellitus. Biol Trace Elem Res. 2019; 188(1):68–98. 10.1007/s12011-018-1540-6 30350272
28 Adachi A, Ogawa K, Tsushi Y, Nagao N, Okano T. Balance, excretion and tissue distribution of vanadium in rats after short-term ingestion. J Health Sci. 2000; 46(1):59–62. 10.1248/jhs.46.59
29 Bogden JD, Higashino H, Lavenhar MA, Bauman JW Jr, Kemp FW, Aviv A. Balance and tissue distribution of vanadium after short-term ingestion of vanadate. J Nutr. 1982; 112(12):2279–2285. 10.1093/jn/112.12.2279 6923926
30 Parker RD, Sharma RP. Accumulation and depletion of vanadium in selected tissues of rats treated with vanadyl sulfate and sodium orthovanadate. J Environ Pathol Toxicol. 1978; 2(2):235–245. 739212
31 Hamel FG, Duckworth WC. The relationship between insulin and vanadium metabolism in insulin target tissues. Mol Cell Biochem. 1995; 153(1-2):95–102. 10.1007/BF01075923 8927053
32 Ramanadham S, Heyliger C, Gresser MJ, Tracey AS, McNeill JH. The distribution and half-life for retention of vanadium in the organs of normal and diabetic rats orally fed vanadium(IV) and vanadium(V). Biol Trace Elem Res. 1991; 30(2):119–124. 10.1007/BF02990348 1723884
33 Azay J, Brès J, Krosniak M, Teissedre PL, Cabanis JC, Serrano JJ, Cros G. Vanadium pharmacokinetics and oral bioavailability upon single-dose administration of vanadyl sulfate to rats. Fundam Clin Pharmacol. 2001; 15(5):313–324. 10.1046/j.1472-8206.2001.00043.x 11903500
34 Paternain JL, Domingo JL, Gómez M, Ortega A, Corbella J. Developmental toxicity of vanadium in mice after oral administration. J Appl Toxicol. 1990; 10(3):181–186. 10.1002/jat.2550100307 2380479
35 Dimond EG, Caravaca J, Benchimol A. Vanadium, excretion, toxicity, lipid effect in man. Am J Clin Nutr. 1963; 12(1):49–53. 10.1093/ajcn/12.1.49 14027941
36 Willsky GR, Halvorsen K, Godzala ME 3rd, Chi LH, Most MJ, Kaszynski P, Crans DC, Goldfine AB, Kostyniak PJ. Coordination chemistry may explain pharmacokinetics and clinical response of vanadyl sulfate in type 2 diabetic patients. Metallomics. 2013; 5(11):1491–1502. 10.1039/c3mt00162h 23982218
37 Mutlu E, Cristy T, Graves SW, Hooth MJ, Waidyanatha S. Characterization of aqueous formulations of tetra- and pentavalent forms of vanadium in support of test article selection in toxicology studies. Environ Sci Pollut Res Int. 2017; 24(1):405–416. 10.1007/s11356-016-7803-x 27726079
38 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
39 Boorman GA, Haseman JK, Waters MD, Hardisty JF, Sills RC. Quality review procedures necessary for rodent pathology databases and toxicogenomic studies: The National Toxicology Program experience. Toxicol Pathol. 2002; 30(1):88–92. 10.1080/01926230252824752 11890481
40 Waidyanatha S, Weber FX, Fallacara DM, Harrington JM, Levine K, Robinson VG, Sparrow BR, Stout MD, Fernando R, Hooth MJ, et al. Systemic exposure and urinary excretion of vanadium following perinatal subchronic exposure to vanadyl sulfate and sodium metavanadate via drinking water. Toxicol Lett. 2022; 360:53–61. 10.1016/j.toxlet.2022.03.004 35331842
41 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
42 Armitage P. Statistical methods in medical research. Oxford, UK: Blackwell Scientific; 1971.
43 Dixon WJ, Massey FJ. Introduction to statistical analysis. 2nd ed. New York, NY: McGraw-Hill; 1957. 10.2307/2332898
44 Tukey J. Easy summaries—numerical and graphical. In: Exploratory Data Analysis. Reading, MA: Addison-Wesley; 1977. p. 27–56.
45 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
46 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
47 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
48 Hsu JC. The factor analytic approach to simultaneous inference in the general linear model. J Comput Graph Stat. 1992; 1(2):151–168.
49 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
50 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
51 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
52 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1-2):133–145. 10.1093/biomet/41.1-2.133
53 Davison AC, Hinkley DV. Bootstrap methods and their application. Cambridge, UK: Cambridge University Press; 1997. 10.1017/CBO9780511802843
54 Datta S, Satten GA. Rank-sum tests for clustered data. J Am Stat Assoc. 2005; 100(471):908–915. 10.1198/016214504000001583
55 Hommel G. A stagewise rejective multiple test procedure based on a modified Bonferroni test. Biometrika. 1988; 75(2):383–386. 10.1093/biomet/75.2.383
56 Hothorn LA. Statistical evaluation of toxicological bioassays – a review. Toxicol Res (Camb). 2014; 3(6):418–432. 10.1039/C4TX00047A
57 Kalbfleisch JD, Lawless JF. The analysis of panel data under a Markov assumption. J Am Stat Assoc. 1985; 80(392):863–871. 10.1080/01621459.1985.10478195
58 Code of Federal Regulations (CFR). 21(Part 58).
59 Miller JA, Miller EC. Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH, Watson JD, Winsten JA, editors. Origins of Human Cancer. Cold Spring Harbor, NY: Cold Spring Harbor Laboratory; 1977. p. 605–627.
60 Crawford BD. Perspectives on the somatic mutation model of carcinogenesis. In: Flamm WG, Lorentzen RJ, editors. Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton, NJ: Princeton Scientific Publishing; 1985. p. 13–59.
61 Straus DS. Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981; 67(2):233–241. 7021938
62 Ashby J, Tennant RW. Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the U.S. NTP. Mutat Res. 1991; 257(3):229–306. 10.1016/0165-1110(91)90003-E 1707500
63 Tennant RW, Margolin BH, Shelby MD, Zeiger E, Haseman JK, Spalding J, Caspary W, Resnick M, Stasiewicz S, Anderson B, et al. Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987; 236(4804):933–941. 10.1126/science.3554512 3554512
64 Zeiger E, Haseman JK, Shelby MD, Margolin BH, Tennant RW, Holden HE. Evaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: Confirmation of earlier results with 41 additional chemicals. Environ Mol Mutagen. 1990; 16 Suppl 18:1–14. 10.1002/em.2850160502 2091921
65 Heddle JA, Hite M, Kirkhart B, Mavournin K, MacGregor JT, Newell GW, Salamone MF. The induction of micronuclei as a measure of genotoxicity: A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983; 123(1):61–118. 10.1016/0165-1110(83)90047-7 6888413
66 Schmid W. The micronucleus test. Mutat Res. 1975; 31(1):9–15. 10.1016/0165-1161(75)90058-8 48190
67 Shelby MD, Erexson GL, Hook GJ, Tice RR. Evaluation of a three-exposure mouse bone marrow micronucleus protocol: Results with 49 chemicals. Environ Mol Mutagen. 1993; 21(2):160–179. 10.1002/em.2850210210 8444144
68 Shelby MD, Witt KL. Comparison results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutagen. 1995; 25(4):302–313. 10.1002/em.2850250407 7607185
69 Witt KL, Knapton A, Wehr CM, Hook GJ, Mirsalis J, Shelby MD, MacGregor JT. Micronucleated erythrocyte frequency in peripheral blood of B6C3F(1) mice from short-term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutagen. 2000; 36(3):163–194. 10.1002/1098-2280(2000)36:3<163:AID-EM1>3.0.CO;2-P 11044899
70 National Toxicology Program (NTP). TOX-106: Toxicity report tables & curves: Pathology tables, survival and growth curves from NTP short-term and genetic toxicology studies. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2023. 10.22427/NTP-DATA-TOX-106
71 National Toxicology Program (NTP). Modified one-generation study of 2-ethylhexyl p-methoxycinnamate (CASRN 5466-77-3) administered in feed to Sprague Dawley (Hsd:Sprague Dawley® SD®) rats with prenatal, reproductive performance, and subchronic assessments in F1 offspring. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2022. NTP Developmental and Reproductive Toxicity (DART) Technical Report No. 06. https://ntp.niehs.nih.gov/go/dart06abs
72 National Toxicology Program (NTP). Modified one-generation study of bisphenol AF (CASRN 1478-61-1) administered in feed to Sprague Dawley (Hsd:Sprague Dawley® SD®) rats with prenatal, reproductive performance, and subchronic assessments in F1 offspring. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2022. NTP Developmental and Reproductive Toxicity (DART) Technical Report No. 08. https://ntp.niehs.nih.gov/go/dart08abs
73 Harrington JM, Haines LG, Levine KE, Liyanapatirana C, Essader AS, Fernando RA, Robinson VG, Roberts GK, Stout MD, Hooth MJ, et al. Internal dose of vanadium in rats following repeated exposure to vanadyl sulfate and sodium orthovanadate via drinking water. Toxicol Appl Pharmacol. 2021; 412:115395. 10.1016/j.taap.2021.115395 33421504
74 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of nondecolorized whole leaf extract of Aloe barbadensis Miller (aloe vera) in F344/N rats and B6C3F1 mice (drinking water studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2013. NTP Technical Report No. 577. NIH Publication No. 13-5910. https://ntp.niehs.nih.gov/go/tr577abs
75 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of sodium dichromate dihydrate (CAS No. 7789-12-0) in F344/N rats and B6C3F1 mice (drinking water studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2008. NTP Technical Report No. 546. NIH Publication No. 08-5887. https://ntp.niehs.nih.gov/go/tr546abs
76 National Toxicology Program (NTP). Toxicity studies of sodium dichromate dihydrate (CAS No. 7789-12-0) administered in drinking water to male and female F344/N rats and B6C3F1 mice and male BALB/c and am3-C57BL/6 mice. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2007. NTP Toxicity Report No. 72. NIH Publication No. 07-5964. https://ntp.niehs.nih.gov/go/tox72abs
77 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of D&C Yellow No. 11 (CAS No. 8003-22-3) in F344/N rats (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1997. NTP Technical Report No. 463. NIH Publication No. 97-3379. https://ntp.niehs.nih.gov/go/tr463abs
78 Boudreau MD, Mellick PW, Olson GR, Felton RP, Thorn BT, Beland FA. Clear evidence of carcinogenic activity by a whole-leaf extract of Aloe barbadensis Miller (aloe vera) in F344/N rats. Toxicol Sci. 2013; 131(1):26–39. 10.1093/toxsci/kfs275 22968693
79 Boudreau MD, Olson GR, Tryndyak VP, Bryant MS, Felton RP, Beland FA. From the cover: Aloin, a component of the aloe vera plant leaf, induces pathological changes and modulates the composition of microbiota in the large intestines of F344/N male rats. Toxicol Sci. 2017; 158(2):302–318. 10.1093/toxsci/kfx105 28525602
80 National Toxicology Program (NTP). Toxicity studies of cobalt sulfate heptahydrate (CAS No. 10026-24-1) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1991. NTP Toxicity Report No. 05. NIH Publication No. 91-3124. https://ntp.niehs.nih.gov/go/tox05abs
81 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of cobalt sulfate heptahydrate (CAS No. 10026-24-1) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1998. NTP Technical Report No. 471. NIH Publication No. 98-3961. https://ntp.niehs.nih.gov/go/tr471abs
82 National Toxicology Program (NTP). Toxicology studies of cobalt metal (CASRN 7440-48-4) in F344/N rats and B6C3F1/N mice and toxicology and carcinogenesis studies of cobalt metal in F344/NTac rats and B6C3F1/N mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2014. NTP Technical Report No. 581. https://ntp.niehs.nih.gov/go/tr581abs
83 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of nickel oxide (CAS No. 1313-99-1) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1996. NTP Technical Report No. 451. NIH Publication No. 96-3367. https://ntp.niehs.nih.gov/go/tr451abs
84 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of nickel sulfate hexahydrate (CAS No. 10101-97-0) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1996. NTP Technical Report No. 454. NIH Publication No. 96-3370. https://ntp.niehs.nih.gov/go/tr454abs
85 National Toxicology Program (NTP). Toxicity studies of cupric sulfate (CAS No. 7758-99-8) administered in drinking water and feed to F344/N rats and B6C3F1 mice. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1993. NTP Toxicity Report No. 29. NIH Publication No. 93-3352. https://ntp.niehs.nih.gov/go/tox29abs
86 National Toxicology Program (NTP). Toxicology and carcinogenesis study of dietary zinc (CASRN 5263-02-5) in Sprague Dawley (Hsd:Sprague Dawley® SD®) rats (feed study). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2019. NTP Technical Report No. 592. https://ntp.niehs.nih.gov/go/tr592abs
87 Schofield CJ, Ratcliffe PJ. Oxygen sensing by HIF hydroxylases. Nat Rev Mol Cell Biol. 2004; 5(5):343–354. 10.1038/nrm1366 15122348
88 Gao N, Ding M, Zheng JZ, Zhang Z, Leonard SS, Liu KJ, Shi X, Jiang BH. Vanadate-induced expression of hypoxia-inducible factor 1 alpha and vascular endothelial growth factor through phosphatidylinositol 3-kinase/Akt pathway and reactive oxygen species. J Biol Chem. 2002; 277(35):31963–31971. 10.1074/jbc.M200082200 12070140
89 National Institute of Advanced Industrial Science and Technology (AIST). Spectral Database for Organic Compounds: SDBS-40459. Tokyo, Japan: National Institute of Advanced Industrial Science and Technology; 1999. https://sdbs.db.aist.go.jp/sdbs/cgi-bin/landingpage?sdbsno=40459
90 Sadtler Inorganics Library. YL No. 141. Hercules, CA: Bio-Rad Laboratories.
91 National Institute of Standards and Technology (NIST). NIST Standard Reference Database 69: NIST Chemistry WebBook: IR Spectrum: Sodium metavanadate. Gaithersburg, MD: U.S. Department of Commerce, National Institute of Standards and Technology; 2021. https://webbook.nist.gov/cgi/cbook.cgi?ID=B6000470&Units=SI&Mask=80#IR-Spec
92 Battelle. Powder Diffraction File-4+ release 2009 and the Inorganic Crystal Structure Database/NIST version 2009-2. Columbus, OH: Battelle; 2009.
93 Sadtler Inorganics Library. Reference spectrum for vanadyl sulfate trihydrate: SL No. 1424.
94 Zeiger E, Anderson B, Haworth S, Lawlor T, Mortelmans K. Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992; 19 Suppl 21:2–141. 10.1002/em.2850190603 1541260
95 Witt KL, Livanos E, Kissling GE, Torous DK, Caspary W, Tice RR, Recio L. Comparison of flow cytometry- and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008; 649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571
96 Dertinger SD, Camphausen K, MacGregor JT, Bishop ME, Torous DK, Avlasevich S, Cairns S, Tometsko CR, Menard C, Muanza T, et al. Three‐color labeling method for flow cytometric measurement of cytogenetic damage in rodent and human blood. Environ Mol Mutagen. 2004; 44(5):427–435. 10.1002/em.20075 15517570
97 Kissling GE, Dertinger SD, Hayashi M, MacGregor JT. Sensitivity of the erythrocyte micronucleus assay: Dependence on number of cells scored and inter-animal variability. Mutat Res. 2007; 634(1-2):235–240. 10.1016/j.mrgentox.2007.07.010 17851117