# Discussion

Vanadium occurs naturally in the earth’s crust and is found in coal and petroleum crude oils, which can lead to background and anthropogenic contributions to oral human exposure.^8^ The primary forms of vanadium identified in foodstuff have been characterized and reported to be vanadyl (V^4+^) and vanadate (V^5+^), likely because they are the more stable oxidation states.^10^ The studies reported here were designed to address data needs for V^4+^ and V^5+^ compounds under comparable experimental designs and test settings. Vanadyl sulfate and sodium metavanadate were selected as representative test articles for the V^4+^ and V^5+^ forms, respectively. The studies describe 3-month drinking water evaluations of both test articles in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats (including a perinatal phase) and B6C3F1/N mice.

Drinking water concentrations of the test articles ranged from 0 to 500 mg/L and from 0 to 335 mg/L for sodium metavanadate and vanadyl sulfate, respectively. There were notable reductions in water consumption at the highest concentration of both test articles for rats and mice, ranging from 10% to 28% (study average; postnatal day 28–112 [rats] and study day 0–91 [mice]) compared to the respective control groups. Table 39 lists the approximate daily dose of vanadium intake across studies as calculated using water consumption and percent vanadium by test article. Vanadium intake for a given compound across both species and sexes was similar. Furthermore, when comparing vanadium intake between the two test articles, intake was similar for the four lowest concentrations of sodium metavanadate and the four highest concentrations of vanadyl sulfate. For example, in male rats, vanadium intake at 31.3 mg/L sodium metavanadate (1.2 mg vanadium/kg/day) was similar to vanadium intake at 41.9 mg/L vanadyl sulfate (1.2 mg vanadium/kg/day).

Table 39 Daily Vanadium (mg/kg) Intake Based on Water Consumption

Test Compound (mg/L) | Vanadium (mg/L)^a^ | Vanadium Intake (mg/kg/day)^b^ | | Vanadium Intake (mg/kg/day)^c^
Test Compound (mg/L) | Vanadium (mg/L)^a^ | Male Rats | Female Rats | Male Mice | Female Mice
Sodium Metavanadate
0 | 0.0 | 0.0 | 0.0 | 0.0 | 0.0
31.3 | 13.1 | 1.2 | 1.3 | 1.4 | 1.3
62.5 | 26.1 | 2.3 | 2.7 | 2.8 | 2.8
125 | 52.1 | 4.5 | 5.3 | 5.5 | 5.6
250 | 104.3 | 8.0 | 8.9 | 11.1 | 10.8
500 | 208.5 | 15.1 | 15.8 | 19.4 | 19.0
Vanadyl Sulfate
0 | 0.0 | 0.0 | 0.0 | 0.0 | 0.0
21.0 | 6.5 | 0.6 | 0.6 | 0.7 | 0.7
41.9 | 13.0 | 1.2 | 1.4 | 1.5 | 1.3
83.8 | 26.0 | 2.2 | 2.9 | 3.0 | 2.6
168 | 52.1 | 4.3 | 5.3 | 6.2 | 5.3
335 | 103.9 | 7.8 | 9.3 | 10.7 | 10.7

^a^ Concentration of vanadium in drinking water calculated using vanadium composition per test article: 41.7% for sodium metavanadate and 31% for vanadyl sulfate.

^b^ Calculated as vanadium concentration (mg/L) × water consumed (g/kg/day; postnatal day 28–112) and a solution density of 1 g/mL.

^c^ Calculated as vanadium concentration (mg/L) × water consumed (g/kg/day; study day 0–91) and a solution density of 1 g/mL.

There was a consistent response across studies when evaluating the dose response of certain effects. An example is in Figure 6, which shows the percent incidence of hyperplasia in the ileum epithelium against vanadium intake (mg/kg/day) in all studies. Overall, the dose response for this endpoint follows a common trend, with the exception of the sodium metavanadate-male mice (SM-MM) study, which shows a shallower dose response and lower maximal effect.

Figure 6

Percent Incidence of Epithelial Hyperplasia in the Ileum of Male and Female Rats and Mice Exposed to Sodium Metavanadate or Vanadyl Sulfate

SM = sodium metavanadate; VS = vanadyl sulfate; MR = male rats; FR = female rats; MM = male mice; FM = female mice.

The lowest-observed-effect levels (LOELs) for each study are shown in Table 40. The most sensitive endpoints tended to be related to erythrocyte microcytosis or epithelial hyperplasia of the gastrointestinal tract (largely the ileum). Erythrocyte microcytosis was observed in male mice exposed to the lowest concentration of sodium metavanadate; consequently, a no-observed-effect level was not obtained.

Table 40 Lowest-Observed-Effect Levels in Male and Female Rats and Mice in the Three-month Drinking Water Studies of Sodium Metavanadate and Vanadyl Sulfate

| Male Rats | Female Rats | Male Mice | Female Mice
Sodium Metavanadate
LOEL
Test article | 125 mg/L | 125 mg/L | 31.3 mg/L | 62.5 mg/L
Vanadium intake | 4.5 mg/kg/day | 5.3 mg/kg/day | 1.4 mg/kg/day | 2.8 mg/kg/day
Endpoint | Hematology Clinical chemistry Histopathology | Histopathology | Hematology | Hematology
Effects^a^ | ↓ MCV ↑ Erythrocytes ↓ Cholesterol ↑ Ileum, epithelium hyperplasia ↑ Jejunum, epithelium hyperplasia | ↑ Ileum, epithelium hyperplasia ↑ Jejunum, epithelium hyperplasia | ↓ MCV | ↓ MCV
Vanadyl Sulfate
LOEL
Test article | 168 mg/L | 168 mg/L | 83.8 mg/L | 83.8 mg/L
Vanadium intake | 4.3 mg/kg/day | 5.3 mg/kg/day | 3.0 mg/kg/day | 2.6 mg/kg/day
Endpoint | Histopathology | Histopathology | Histopathology | Hematology Histopathology
Effects | ↑ Ileum, epithelium hyperplasia | ↑ Ileum, epithelium hyperplasia | ↑ Ileum, epithelium hyperplasia | ↑ Erythrocytes ↑ Ileum, epithelium hyperplasia

LOEL = lowest-observed-effect level; MCV = mean cell volume.

^a^ Selected LOELs for hematology are based on statistical significance. In some cases, histopathology LOELs reached statistical significance; however, significance was not required given there was no background incidence of the observed lesions. Effects considered secondary to dehydration (e.g., increased blood urea nitrogen) were not included.

In general, when considering vanadium intake, no consistent pattern was observed across all studies to indicate that total vanadium or test article oxidation state were major drivers for determining the dose at which effects occurred. In rats, the effect levels for histopathology between test articles aligned well with total consumed vanadium (Figure 7), indicating that total vanadium, rather than vanadium oxidation state, may be a driver for toxicity. For example, the calculated vanadium dose at which histopathological effects were seen ranged from 4.3 to 5.3 mg vanadium/kg/day for male and female rats exposed to either test article. However, there were some endpoints for which an effect was observed only in sodium metavanadate-exposed rats (e.g., hematology, clinical chemistry, and reduced dam and pup survival). This may be in part due to absorption, distribution, metabolism, and excretion differences between V^4+^ and V^5+^ compounds, wherein, at the end of these 3-month studies, up to threefold higher concentrations of vanadium in plasma and urine (measured in rats only) were observed in rats exposed to sodium metavanadate compared to rats exposed to vanadyl sulfate, when normalizing for vanadium intake per day (i.e., mg vanadium/day).^40^ This pattern of higher concentrations of vanadium in plasma and urine from V^5+^ exposure compared to V^4+^ was also seen in shorter-term studies conducted as part of a National Toxicology Program (NTP) research program.^73^ In mice, total vanadium intake did not seem to dictate the level at which an effect occurred. For both male and female mice, histopathology effects were observed at different calculated vanadium doses when comparing test articles (e.g., in female mice, the vanadyl sulfate LOEL for histopathology was 2.6 mg vanadium/kg/day versus the sodium metavanadate LOEL that was 5.6 mg vanadium/kg/day).

Figure 7

Effect Levels across Endpoints for Male and Female Rats and Mice in the Three-month Drinking Water Studies of Sodium Metavanadate or Vanadyl Sulfate

BW = body weight; CC = clinical chemistry; He = hematology; H = histopathology.

The intestinal epithelial hyperplasia observed across both test articles, sexes, and species is an unusual exposure-related lesion, especially in subchronic studies. Examples of NTP studies in which this lesion was observed include the 2-year study of nondecolorized whole-leaf extract of aloe vera in male and female rats (drinking water exposure),^74^ the 3-month and 2-year studies of sodium dichromate dihydrate in male and female mice (drinking water exposure),^75,76^ and the 2-year study of D&C Yellow No. 11 in male rats (feed exposure).^77^ In the D&C Yellow No. 11 studies, hyperplasia of the small intestinal epithelium was observed in F344/N rats in the 2-year core study, but not in the rats from the 12-month interim sacrifice; no neoplasms were observed in the small or large intestine in this study.^77^ After 2 years of exposure via feed in male rats, D&C Yellow No. 11 induced a hyperplastic lesion in the small intestine that resembled that seen in the current study in which there were increased numbers of intestinal epithelial cells (not goblet cells) lining the small intestine. There were no neoplastic lesions in the small intestine, however. It is possible that, given more time, exposure to D&C Yellow No. 11 may have resulted in neoplasms of the small intestine. In the sodium dichromate dihydrate studies (mice only), exposure to the test article via drinking water for 2 years resulted in neoplasms of the small intestine (all segments combined). These neoplasms were accompanied by hyperplasia of the small intestinal epithelium,^75^ which was also observed in the 3-month studies.^76^ The hyperplastic lesions in the small intestine were morphologically similar to that seen in the current study.

Three months of exposure to aloe vera extract in male and female F344/N rats and B6C3F1 mice and aloin in male F344/N rats mainly induced goblet cell hyperplasia in the large intestine.^78,79^ Goblet cell hyperplasia was not seen in the current study. In rats, 3 months of exposure to aloin or aloe vera extract resulted in mucosal hyperplasia of the large and small intestines, although it was much more prevalent in the large intestine.^78,79^ In studies on aloe vera nondecolorized whole-leaf extract, exposure for 3 months resulted in goblet cell hyperplasia in the large intestine of male and female F344/N rats and B6C3F1 mice.^74^ In male and female rats, exposure for 2 years resulted in mucosa hyperplasia in the small and large intestines and neoplasms of the large intestine The mucosal hyperplasia in the large intestine induced by aloe vera appeared to be a thickened mucosal layer due to elongation of the crypts. No further description was provided. In the current study, the hyperplasia in the small and large intestines had a different appearance in that it was characterized by increased numbers of epithelial cells (not goblet cells). Furthermore, the main site of the hyperplasia in the current study was the ileum, with lower incidences in adjacent intestinal segments. The site of neoplasia in the aloe vera study at 2 years and the site with the highest incidence of hyperplasia after 13 weeks was the colon, which also differed from the current study.

The data from the sodium dichromate dihydrate and aloe vera studies suggest an association between hyperplasia and neoplasms, but this is not supported by the D&C Yellow No. 11 studies in which no neoplasms developed following 2 years of exposure. In all of these studies, however, intestinal epithelial hyperplasia was observed at the subchronic time point only in the sodium dichromate dihydrate study, exemplifying the rarity of seeing this lesion in a 3-month study. While the D&C Yellow No. 11 study shows that intestinal epithelial hyperplasia may not lead to neoplasia, the other two studies suggest such an association. Perhaps the most comparable studies are the sodium dichromate dihydrate studies because both sodium dichromate dihydrate and the vanadium compounds in the current study are metals, and they both resulted in hyperplastic intestinal lesions in mice. Therefore, given the similar appearance of these hyperplastic lesions to those seen in the sodium dichromate dihydrate and aloe vera nondecolorized whole-leaf extract studies, it is possible that longer term exposure to sodium metavanadate or vanadyl sulfate may result in the formation of intestinal neoplasms.

In the current drinking water studies, the hematology results indicated that exposure of mice to sodium metavanadate or vanadyl sulfate affected the circulating erythroid mass and resulted in a microcytic erythrocytosis effect. Interestingly, vanadium is one of ten transition metals in the “period 4” row of elements of the periodic table (in order: scandium [Sc], titanium [Ti], vanadium [V], chromium [Cr], manganese [Mn], iron [Fe], cobalt [Co], nickel [Ni], copper [Cu], and zinc [Zn]). Six of those transition elements, including vanadium, have been evaluated (in various forms and exposure paradigms) as part of NTP toxicity and carcinogenicity studies, including vanadium (as vanadium pentoxide),^1^ chromium (as sodium dichromate dihydrate),^75,76^ cobalt (as cobalt sulfate heptahydrate and cobalt metal),^80-82^ nickel (as nickel oxide and nickel sulfate hexahydrate),^83,84^ copper (as cupric sulfate),^85^ and zinc (as dietary zinc).^86^ In all of these NTP studies, there were some significant pairwise microcytic-type changes (either in rats or mice or in males or females). Significantly decreased mean cell volume was observed in the studies of vanadium, chromium, nickel, copper, and zinc, whereas erythrocytosis-type changes (i.e., significantly increased red blood cell count) were observed in the studies of vanadium, chromium, cobalt, nickel, and copper.

While the mechanism of these microcytic- and erythrocytosis-type changes are unknown, the idea that vanadium is in the same period 4 group of transition elements as iron should be considered. Iron is a key component of hemoglobin production. As an essential element of hemoglobin, an alteration in iron metabolism results in an iron deficiency (absolute or functional), which alters erythrocyte production and results in altered numbers and size (e.g., microcytic erythrocytes) of the circulating red blood cells. Iron is also an indispensable cofactor as an essential redox element that functions in many metabolic pathways. For example, the active hypoxia-inducible factor (HIF) hydroxylases, prolyl hydroxylase domains (PHDs), and factor inhibiting HIF (FIH) involved in the regulation of the HIF1α subunit of HIF require iron to be catalytically functional.^87^ Cobalt, another “period 4” transition metal, is a well-known inducer of erythrocytosis in normoxic conditions related to the inhibition of PHDs and FIH, the stabilization of HIF1α, and the stimulation of erythropoietin by HIF1. Indeed, studies have shown that the active-site Fe^2+^ can be substituted by Co^2+^, Cu^2+^, Zn^2+^, and Mn^2+^. Therefore, the classic hypoxia-mimetic function (i.e., eythrocytosis through increased erythropoietin production) of cobalt appears to be explained by its direct inhibition of the HIF hydroxylases.^87^ Interestingly, it has been demonstrated in vitro that the expression of HIF1α was induced by sodium orthovanadate.^88^ Thus, vanadate administration may involve substitution of Fe and affect erythrocyte production through hemoglobin production and/or altered regulation of HIF.

Under the conditions of these studies, oral exposure to sodium metavanadate or vanadyl sulfate in drinking water resulted in hematological effects associated with erythrocyte microcytosis in rats (sodium metavanadate) and mice (sodium metavanadate and vanadyl sulfate), including erythrocytosis in male rats and in male and female mice. Epithelial hyperplasia of the ileum and other gastrointestinal sites was observed histologically, which was consistent for both test articles and across both sexes and species evaluated. In the sodium metavanadate studies, the LOELs were 125 mg/L in male and female rats, 31.3 mg/L in male mice, and 62.5 mg/L in female mice, based on changes in hematology (male rats and male and female mice) and epithelium hyperplasia in the ileum and jejunum (male and female rats). In the vanadyl sulfate studies, the LOELs were 168 mg/L in male and female rats and 83.8 mg/L in male and female mice, as indicated by epithelium hyperplasia in the ileum (male and female rats and mice) and hematology (female mice).