# Results

## Data Availability

All study data were evaluated. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TOX-106.^70^

## Sodium Metavanadate

### Rats

#### Three-month Study (Perinatal Phase)

Around the time of parturition and shortly thereafter (approximately gestation day [GD] 22 to lactation day [LD] 4), adverse clinical signs (e.g., lethargy, hunched posture, and pallor) and exposure-related mortalities were observed in dams in the 250 and 500 mg/L groups (Appendix E). Higher dam mortality was also observed in later lactation (LD 5–25) in the 500 mg/L group. Due to early deaths, moribund euthanasia, and whole litter losses, nine dams and their respective litters in the 500 mg/L group were removed during late gestation or early lactation (Table 4). Three additional dams were removed in early lactation due to insufficient litter size. These removals collectively resulted in only four dams (and litters) at the end of lactation in the 500 mg/L group available to populate the postweaning study. Three dams in the 250 mg/L group were removed because of moribundity, and an additional dam in the 250 mg/L group was found dead. Two dams in the 125 mg/L group were removed from the study in early lactation due to moribundity and whole litter loss.

Table 4 Summary of the Disposition of F_0_ Female Rats during Perinatal Exposure in the Perinatal and Three-month Drinking Water Study of Sodium Metavanadate

Reproductive Performance | 0 mg/L | 31.3 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L
Time-mated Females (GD 6) | 16 | 16 | 16 | 16 | 16 | 16
Females Pregnant (%)^a^ | 16 (100) | 14 (87.5) | 16 (100) | 16 (100) | 15 (93.8) | 16 (100)
Females Not Pregnant (%) | 0 (0) | 2 (12.5) | 0 (0) | 0 (0) | 1 (6.25) | 0 (0)
Pregnant Females Removed Prior to Littering (%)^b^ | 0 (0) | 0 (0) | 0 (0) | 0 (0) | 2 (13.3) | 1 (6.25)
Dams with Litters on LD 0 (%)^b^ | 16 (100) | 14 (100) | 16 (100) | 16 (100) | 13 (100) | 15 (100)
Gestation Length (Days)^c,d^ | 22.1 ± 0.1 (16) | 22.3 ± 0.2 (14) | 22.0 ± 0.0 (16) | 22.2 ± 0.1 (16) | 22.0 ± 0.1 (13) | 22.5 ± 0.2 (15)
Litters Poststandardization (PND 4)^e^ | 15 | 12 | 14 | 14 | 11 | 8^f^
Litters at Weaning (PND 28) | 15 | 12 | 14 | 14 | 11 | 4^g^
F_1_ Males/Females (PND 28)^h^ | 57/63 | 44/52 | 52/59 | 56/55 | 45/35 | 13/12

GD = gestation day; LD = lactation day; PND = postnatal day.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^b^ Percentage is given as a portion of pregnant dams.

^c^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^d^ Gestation length calculated for sperm-positive females that delivered a litter. Data are presented as mean ± standard error (number of dams).

^e^ Standardization to eight pups/litter (four pups/sex).

^f^ There were seven exposure-related dam and respective litter removals between LD 0 and LD 4 (poststandardization): two dams euthanized moribund on LD 0, one whole litter loss on PND 1 and PND 4, and three removed during standardization on LD 4 due to insufficient litter sizes (less than four total pups) resulting from high pup mortality (PND 0–4).

^g^ There were four exposure-related dam and respective litter removals between LD 4 (poststandardization) and LD 25: one dam found dead on LD 5 and one on LD 20 and one dam euthanized moribund on LD 7 and one on LD 25.

^h^ Number of males/females surviving until weaning on PND 28.

Beginning on GD 12, dams in the 250 and 500 mg/L groups had significantly decreased body weights compared to that of the control group, and on GD 21, significantly decreased body weights were observed in exposed groups ≥125 mg/L, with a 14% decrease at 500 mg/L (Table 5). Decreased body weights persisted during lactation in the 250 and 500 mg/L groups until LDs 21 and 25, respectively, after which the body weights were no longer different from those of the control group, indicating recovery.

Table 5 Summary of Body Weights and Body Weight Gains of F_0_ Female Rats during Gestation and Lactation in the Perinatal and Three-month Drinking Water Study of Sodium Metavanadate

Parameter^a,b^ | 0 mg/L | 31.3 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L
Gestation Body Weight
Gestation Day
6 | 242.1 ± 2.4 (16) | 237.8 ± 3.1 (14) | 240.7 ± 3.2 (16) | 240.3 ± 3.1 (16) | 240.9 ± 3.6 (15) | 239.2 ± 3.1 (16)
9 | 253.5 ± 2.9* (16) | 249.7 ± 3.8 (14) | 250.6 ± 3.3 (16) | 248.1 ± 3.3 (16) | 245.8 ± 3.0 (15) | 243.9 ± 2.5 (16)
12 | 272.2 ± 2.9** (16) | 269.7 ± 3.6 (14) | 266.3 ± 3.5 (16) | 261.4 ± 3.3* (16) | 257.1 ± 2.9** (15) | 256.2 ± 2.4** (16)
15 | 290.7 ± 3.0** (16) | 286.5 ± 3.7 (14) | 286.0 ± 3.8 (16) | 281.1 ± 4.0 (16) | 275.6 ± 3.2** (15) | 271.9 ± 2.8** (16)
18 | 333.8 ± 3.8** (16) | 325.3 ± 5.5 (14) | 326.5 ± 5.2 (16) | 320.8 ± 5.6 (16) | 308.7 ± 4.8** (15) | 307.7 ± 4.0** (16)
21 | 385.0 ± 4.0** (16) | 368.2 ± 7.9 (14) | 373.3 ± 7.2 (16) | 360.0 ± 8.6* (16) | 348.9 ± 5.3** (14) | 330.8 ± 6.6** (16)
Gestation Weight Change
Gestation Day Interval
6–9 | 11.4 ± 1.1** (16) | 11.8 ± 2.5 (14) | 9.9 ± 0.7 (16) | 7.8 ± 1.6 (16) | 4.9 ± 1.6** (15) | 4.8 ± 1.2** (16)
9–12 | 18.7 ± 0.7** (16) | 20.0 ± 1.0 (14) | 15.6 ± 0.8* (16) | 13.4 ± 1.0** (16) | 11.3 ± 0.8** (15) | 12.3 ± 1.0** (16)
12–15 | 18.5 ± 0.6 (16) | 16.8 ± 1.4 (14) | 19.8 ± 1.3 (16) | 19.7 ± 1.6 (16) | 18.5 ± 1.1 (15) | 15.7 ± 1.5 (16)
15–18 | 43.1 ± 1.3** (16) | 38.8 ± 2.8 (14) | 40.5 ± 2.9 (16) | 39.7 ± 2.5 (16) | 33.1 ± 4.3* (15) | 35.8 ± 2.3* (16)
18–21 | 51.2 ± 1.1** (16) | 42.9 ± 3.6 (14) | 46.8 ± 2.8 (16) | 39.3 ± 4.4* (16) | 37.3 ± 3.9* (14) | 23.1 ± 5.7** (16)
6–21 | 142.9 ± 2.5** (16) | 130.4 ± 7.3 (14) | 132.6 ± 6.7 (16) | 119.7 ± 7.9* (16) | 109.5 ± 5.9** (14) | 91.6 ± 7.5** (16)
Lactation Body Weight
Lactation Day
1 | 282.9 ± 3.1** (16) | 280.1 ± 4.0 (14) | 275.4 ± 4.5 (16) | 270.2 ± 4.4 (15) | 263.1 ± 3.3** (11) | 243.8 ± 7.5** (12)
4 | 297.6 ± 3.2** (16) | 290.4 ± 3.8 (14) | 292.1 ± 4.8 (16) | 280.4 ± 5.0 (14) | 268.7 ± 3.9** (11) | 220.2 ± 13.6** (12)
7 | 305.5 ± 3.9** (15) | 303.9 ± 4.2 (12) | 300.1 ± 5.3 (14) | 288.5 ± 4.1* (14) | 279.8 ± 4.5** (11) | 250.6 ± 14.1** (7)
10 | 314.0 ± 4.3** (15) | 314.4 ± 4.5 (12) | 309.4 ± 5.4 (14) | 303.0 ± 4.9 (14) | 293.4 ± 3.8** (11) | 278.9 ± 6.2** (6)
13 | 319.2 ± 3.6** (15) | 316.4 ± 4.2 (12) | 311.2 ± 4.6 (14) | 312.0 ± 5.4 (14) | 295.3 ± 2.8** (11) | 279.2 ± 4.6** (6)
16 | 314.3 ± 4.8** (15) | 320.4 ± 4.5 (12) | 314.1 ± 6.9 (14) | 308.9 ± 4.0 (14) | 297.5 ± 4.1* (11) | 290.0 ± 7.8** (6)
19 | 311.9 ± 5.1** (15) | 316.2 ± 5.1 (12) | 309.3 ± 7.1 (14) | 308.1 ± 4.3 (14) | 299.5 ± 5.4 (11) | 284.7 ± 11.3** (6)
21 | 307.3 ± 3.1** (15) | 311.2 ± 5.2 (12) | 304.6 ± 6.2 (14) | 300.6 ± 3.8 (14) | 287.0 ± 4.4** (11) | 279.1 ± 11.0** (5)
25 | 286.4 ± 3.8* (15) | 289.8 ± 4.2 (12) | 283.2 ± 5.8 (14) | 281.7 ± 4.7 (14) | 278.1 ± 3.5 (11) | 252.7 ± 23.4** (5)
28 | 284.8 ± 4.1 (15) | 287.3 ± 5.4 (12) | 277.4 ± 5.9 (14) | 278.5 ± 4.7 (14) | 275.3 ± 4.6 (11) | 278.8 ± 6.2 (4)
Lactation Weight Change
Lactation Day Interval
1–4 | 14.7 ± 2.2** (16) | 10.3 ± 2.4 (14) | 16.7 ± 2.1 (16) | 9.0 ± 2.8 (14) | 5.6 ± 2.0 (11) | −23.6 ± 8.0** (12)
4–7 | 7.0 ± 1.7 (15) | 11.9 ± 2.4 (12) | 6.5 ± 1.8 (14) | 8.2 ± 3.0 (14) | 11.1 ± 2.3 (11) | −1.0 ± 7.4 (7)
7–10 | 8.5 ± 2.3* (15) | 10.4 ± 1.7 (12) | 9.3 ± 2.5 (14) | 14.5 ± 3.7 (14) | 13.6 ± 2.3 (11) | 14.6 ± 4.7 (6)
10–13 | 5.2 ± 3.2 (15) | 2.0 ± 1.3 (12) | 1.7 ± 2.7 (14) | 9.0 ±2.3 (14) | 1.8 ± 2.6 (11) | 0.3 ± 2.8 (6)
13–16 | −4.9 ± 3.2 (15) | 4.1 ± 2.4 (12) | 3.0 ± 3.6 (14) | −3.1 ± 2.0 (14) | 2.2 ± 2.4 (11) | 10.8 ± 3.5** (6)
16–19 | −2.4 ± 2.7 (15) | −4.3 ± 2.4 (12) | −4.8 ± 1.9 (14) | −0.8 ± 2.0 (14) | 2.0 ± 3.1 (11) | −5.3 ± 15.7 (6)
19–21 | −4.6 ± 3.1 (15) | −5.0 ± 2.1 (12) | −4.7 ± 3.0 (14) | −7.5 ± 2.4 (14) | −12.6 ± 3.8 (11) | −13.7 ± 4.7 (5)
21–25 | −20.9 ± 2.5* (15) | −21.4 ± 2.0 (12) | −21.4 ± 2.2 (14) | −18.9 ± 3.4 (14) | −8.9 ± 3.6 (11) | −26.4 ± 15.2 (5)
25–28 | −1.6 ± 1.4 (15) | −2.5 ± 2.4 (12) | −5.8 ± 1.9 (14) | −3.2 ± 2.1 (14) | −2.7 ± 1.9 (11) | 3.3 ± 6.6 (4)
4–28 | −13.7 ± 3.4** (15) | −4.8 ± 3.1 (12) | −16.3 ± 2.2 (14) | −1.9 ± 3.2* (14) | 6.6 ± 4.8** (11) | 23.2 ± 2.3** (4)
1–28 | 0.6 ± 3.2** (15) | 5.3 ± 2.9 (12) | 1.1 ± 3.2 (14) | 7.1 ± 3.5 (14) | 12.2 ± 3.8* (11) | 18.9 ± 4.4** (4)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Each exposed group was compared to the vehicle control group with the Williams test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunnett test when no trend was present.

^b^ Data are presented as mean ± standard error (number of dams). Body weight data are presented in grams.

Water consumption (g water/kg body weight/day) was significantly decreased during gestation (GD 6–21) in groups ≥125 mg/L in a concentration-dependent manner, reaching a 37% decrease at 500 mg/L (Table 6). Water consumption began to increase in these groups during lactation, with an average 7% decrease in the 500 mg/L group compared to the control group from LD 1 to LD 13. Water consumption by groups ≤250 mg/L was similar to the control group during lactation. Sodium metavanadate intake (mg sodium metavanadate/kg body weight/day) during gestation (GD 6–21) and lactation (LD 1–13) are presented in Table 6. Due to reduced water consumption during gestation, sodium metavanadate intake was less than dose-proportional (10-fold increase in intake versus a 16-fold increase in drinking water concentration from the 31.3 mg/L to 500 mg/L groups).

Table 6 Summary of Water and Sodium Metavanadate Consumption by F_0_ Female Rats during Gestation and Lactation in the Perinatal and Three-month Drinking Water Study

Parameter^a^ | 0 mg/L | 31.3 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L
Gestation Day Interval (g/kg/day)^b^
6–9 | 132.4 ± 3.9** (16) | 131.2 ± 6.0 (14) | 129.2 ± 3.1 (16) | 112.7 ± 2.6** (16) | 96.4 ± 2.9** (15) | 79.7 ± 2.9** (16)
9–12 | 134.5 ± 4.1** (16) | 138.5 ± 6.0 (14) | 137.0 ± 4.2 (16) | 119.7 ± 4.2* (15) | 102.9 ± 5.6** (15) | 82.8 ± 2.2** (16)
12–15 | 133.8 ± 3.8** (16) | 135.3 ± 5.8 (13) | 130.5 ± 4.5 (16) | 120.0 ± 6.2* (16) | 101.0 ± 4.8** (15) | 79.9 ± 2.9** (16)
15–18 | 145.4 ± 3.6** (16) | 143.8 ± 6.5 (14) | 142.7 ± 4.7 (16) | 129.7 ± 5.4* (16) | 116.2 ± 5.2** (15) | 101.6 ± 2.6** (15)
18–21 | 133.8 ± 3.8** (16) | 134.7 ± 8.1 (14) | 128.6 ± 4.2 (16) | 118.5 ± 5.4* (16) | 99.8 ± 7.4** (15) | 83.5 ± 4.7** (16)
6–21 | 134.6 ± 3.4** (16) | 135.5 ± 6.1 (14) | 132.1 ± 3.5 (16) | 119.6 ± 4.4* (16) | 102.7 ± 4.2** (15) | 84.7 ± 2.6** (16)
Lactation Day Interval (g/kg/day)^b^
1–4 | 169.0 ± 11.2 (16) | 166.5 ± 6.5 (13) | 184.1 ± 9.1 (16) | 196.6 ± 7.8 (14) | 172.0 ± 9.5 (11) | 107.4 ± 16.4* (12)
4–7 | 197.1 ± 5.6 (15) | 197.2 ± 6.0 (12) | 206.0 ± 4.3 (14) | 197.3 ± 7.2 (14) | 191.9 ± 11.1 (11) | 156.0 ± 27.1 (7)
7–10 | 224.1 ± 6.9 (14) | 228.5 ± 3.9 (12) | 232.9 ± 5.3 (14) | 227.3 ± 6.7 (14) | 211.3 ± 13.9 (11) | 236.2 ± 13.6 (6)
10–13 | 265.5 ± 9.8** (15) | 250.7 ± 6.2 (12) | 257.3 ± 8.0 (14) | 240.0 ± 4.3 (14) | 221.6 ± 11.7 (11) | 228.0 ± 22.3 (6)
1–13 | 215.0 ± 6.7 (15) | 213.3 ± 4.3 (12) | 224.3 ± 4.8 (14) | 215.9 ± 5.1 (14) | 200.0 ± 10.7 (11) | 199.1 ± 15.4 (6)
Chemical Intake (mg/kg/day)^c,d^
GD 6–21 | 0.0 ± 0.0 (16) | 4.2 ± 0.2 (14) | 8.3 ± 0.2 (16) | 14.9 ± 0.6 (16) | 25.7 ± 1.0 (15) | 42.4 ± 1.3 (16)
LD 1–13 | 0.0 ± 0.0 (15) | 6.7 ± 0.1 (12) | 14.0 ± 0.3 (14) | 27.0 ± 0.6 (14) | 50.0 ± 2.7 (11) | 99.5 ± 7.7 (6)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

GD = gestation day; LD = lactation day.

^a^ Data are presented as mean ± standard error (number of dams).

^b^ Each exposed group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^c^ Chemical intake calculated as: ([exposure concentration × water consumption]/[average body weight of day range]).

^d^ No statistical analysis was performed on the chemical intake data.

Sodium metavanadate exposure had no effect on pregnancy or littering rate. While not reaching statistical significance, the total number and number of live pups per litter on postnatal day (PND) 0 in the 500 mg/L group were lower than control rats by 19% and 25%, respectively (Table 7). The total number and number of live pups per litter on PND 0 in the 250 mg/L group were also slightly lower but within 10% of the control group. Pup viability after PND 4 was lower in the 250 and 500 mg/L groups. The number of live pups per litter was significantly decreased relative to the control group, beginning poststandardization on PND 4 in the 250 and 500 mg/L groups, and there were higher numbers of dead pups per litter and lower survival ratios at all postnatal intervals (PND 0, PND 1–4, PND 5–28) in the 500 mg/L group. Adverse clinical observations in pups in the 500 mg/L group included absence of milk band, pallor, thinness, ruffled coat, and cold to touch (Appendix E). Similar findings were observed in the 250 mg/L group but at a lower incidence.

Table 7 Summary of Litter Size and Survival Ratio of F_1_ Male and Female Rats during Lactation in the Perinatal and Three-month Drinking Water Study of Sodium Metavanadate

Postnatal Day | 0 mg/L | 31.3 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L
Total Litter Size^a,b^
0 | 13 ± 0.4 (16) | 11.1 ± 1.1 (14) | 12.6 ± 1.0 (16) | 12.9 ± 1.0 (16) | 11.8 ± 0.9 (13) | 10.5 ± 0.6 (15)
Live Litter Size^a,b^
0 | 12.3 ± 0.5 (16) | 10.9 ± 1.1 (14) | 12.4 ± 1.0 (16) | 12.9 ± 1.0 (15)^c^ | 11.4 ± 1.0 (11)^c^ | 9.2 ± 1.0 (12)^c^
1 | 12.3 ± 0.6 (16) | 10.6 ± 1.1 (14) | 12.2 ± 1.0 (16) | 12.7 ± 1.0 (15) | 11.3 ± 1.1 (11) | 8.3 ± 1.2 (12)
4 (Prestandardization) | 12.3 ± 0.6 (16) | 10.5 ± 1.1 (14) | 12.2 ± 1.0 (16) | 13.4 ± 0.6 (14)^c^ | 11.1 ± 1.0 (11) | 7.4 ± 1.4 (11)^c^
4 (Poststandardization) | 8.0 ± 0.0** (15)^c^ | 8.0 ± 0.0 (12)^c^ | 8.0 ± 0.0 (14)^c^ | 8.0 ± 0.0 (14) | 7.5 ± 0.4** (11) | 6.8 ± 0.5** (8)^c^
7 | 8.0 ± 0.0** (15) | 8.0 ± 0.0 (12) | 8.0 ± 0.0 (14) | 7.9 ± 0.1 (14) | 7.5 ± 0.4* (11) | 7.0 ± 0.7** (6)^d^
10 | 8.0 ± 0.0** (15) | 8.0 ± 0.0 (12) | 7.9 ± 0.1 (14) | 7.9 ± 0.1 (14) | 7.5 ± 0.4 (11) | 7.0 ± 0.7* (6)
13 | 8.0 ± 0.0** (15) | 8.0 ± 0.0 (12) | 7.9 ± 0.1 (14) | 7.9 ± 0.1 (14) | 7.4 ± 0.4** (11) | 7.0 ± 0.7* (6)
16 | 8.0 ± 0.0** (15) | 8.0 ± 0.0 (12) | 7.9 ± 0.1 (14) | 7.9 ± 0.1 (14) | 7.4 ± 0.4** (11) | 7.0 ± 0.7* (6)
19 | 8.0 ± 0.0** (15) | 8.0 ± 0.0 (12) | 7.9 ± 0.1 (14) | 7.9 ± 0.1 (14) | 7.3 ± 0.4** (11) | 7.0 ± 0.7* (6)
21 | 8.0 ± 0.0** (15) | 8.0 ± 0.0 (12) | 7.9 ± 0.1 (14) | 7.9 ± 0.1 (14) | 7.3 ± 0.4** (11) | 6.4 ± 0.9** (5)^d^
25 | 8.0 ± 0.0** (15) | 8.0 ± 0.0 (12) | 7.9 ± 0.1 (14) | 7.9 ± 0.1 (14) | 7.3 ± 0.4** (11) | 5.8 ± 1.0** (5)
28 | 8.0 ± 0.0** (15) | 8.0 ± 0.0 (12) | 7.9 ± 0.1 (14) | 7.9 ± 0.1 (14) | 7.3 ± 0.4** (11) | 6.3 ± 1.1** (4)^d^
% Live Male per Litter^a,b,e^
0 | 41.59 ± 3.04** (16) | 50.62 ± 5.06 (14) | 47.18 ± 3.87 (16) | 53.68 ± 4.91* (15) | 62.28 ± 3.42** (11) | 54.84 ± 5.67** (12)
No. of Dead Pups (Litters)^f,g^
0 | 11 (3) | 3 (2) | 3 (2) | 13 (5) | 29 (3) | 47 (7)
1–4 | 1 (1) | 5 (3) | 3 (3) | 7 (7) | 3 (3) | 29 (5)
5–28 | 0 (0) | 0 (0) | 1 (1) | 1 (1) | 2 (2) | 9 (4)
Dead per Litter^a,b,h^
0 | 0.69 ± 0.44* (16) | 0.21 ± 0.15 (14) | 0.19 ± 0.14 (16) | 0.81 ± 0.50 (16) | 2.23 ± 1.45 (13) | 3.13 ± 1.17 (15)
1–4 | 0.06 ± 0.06** (16) | 0.36 ± 0.23 (14) | 0.19 ± 0.10 (16) | 0.47 ± 0.13 (15) | 0.27 ± 0.14 (11) | 2.42 ± 1.08* (12)
5–28 | 0.00 ± 0.00** (15) | 0.00 ± 0.00 (12) | 0.07 ± 0.07 (14) | 0.07 ± 0.07 (14) | 0.18 ± 0.12 (11) | 1.80 ± 1.07** (5)
Survival Ratio^a,b^
0^i^ | 0.95 ± 0.03* (16) | 0.98 ± 0.01 (14) | 0.99 ± 0.01 (16) | 0.91 ± 0.06 (16) | 0.84 ± 0.10 (13) | 0.70 ± 0.11 (15)
1–4^j^ | 0.99 ± 0.01** (16) | 0.97 ± 0.02 (14) | 0.96 ± 0.03 (16) | 0.90 ± 0.07 (15) | 0.97 ± 0.02 (11) | 0.73 ± 0.10* (12)
5–28^k^ | 1.00 ± 0.00** (15) | 1.00 ± 0.00 (12) | 0.99 ± 0.01 (14) | 0.99 ± 0.01 (14) | 0.98 ± 0.02 (11) | 0.70 ± 0.18** (5)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean of the litter means ± standard error (number of litters).

^b^ Each exposed group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^c^ There were 16 dam and respective litter removals between lactation day (LD) 0 and LD 4 (poststandardization). One dam in the control group and two in both the 31.3 mg/L and 62.5 mg/L groups were removed during standardization on LD 4 due to insufficient litter sizes (less than four total pups). In the 125 mg/L group, one dam was euthanized moribund on LD 0, and one whole litter loss occurred on LD 3. In the 250 mg/L group, one whole litter loss occurred on LD 0 and the respective dam was euthanized on LD 1, and one dam was euthanized moribund on LD 0. In the 500 mg/L group, one whole litter loss occurred on LD 0 and the respective dam was euthanized on LD 1, two dams were euthanized moribund on LD 0, one whole litter loss occurred on LD 1 and one on LD 4, and three dams and their respective litters were removed during standardization on LD 4 due to insufficient litter sizes resulting from high pup mortality (LD 0–4).

^d^ There were four dam and respective litter removals between LD 4 (poststandardization) and LD 25. In the 500 mg/L group, one dam was found dead on LD 5 and one on LD 20, and one dam was euthanized moribund on LD 7 and one on LD 25.

^e^ 100 × [number of live males in exposure group]/[number of live males and females in exposure group](number of pups).

^f^ Total number of dead pups in exposure group (number of litters contributing dead pups).

^g^ No statistical analysis was performed on this endpoint.

^h^ Number dead per litter (number of litters).

^i^ Survival per litter: Number of live pups on postnatal day (PND) 0/total number of pups upon completion of parturition.

^j^ Survival per litter: Number of pups prestandardization on PND 4/total live pups on PND 0.

^k^ Survival per litter: Number of live pups on PND 28/number of live pups poststandardization on PND 4.

Pup body weights at the end of lactation were within 10% of those of the control groups in all exposed groups except the 500 mg/L groups, in which male body weight decreased by 21% and female body weight decreased by 22% compared to the respective control groups (Table 8). Other exposed groups exhibited sporadically significant differences from the control groups throughout lactation but were generally within 10% of the control groups.

Table 8 Summary of Preweaning F_1_ Male and Female Rat Pup Body Weights Following Perinatal Exposure to Sodium Metavanadate

Postnatal Day | 0 mg/L | 31.3 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L
Male
1^a,b,c^ | 7.54 ± 0.07* (81/16) | 7.57 ± 0.19 (68/14) | 7.57 ± 0.12 (93/16) | 7.27 ± 0.16 (98/15) | 7.57 ± 0.16 (76/11) | 6.83 ± 0.27* (55/12)
4^d,e,f,g^ | 10.91 ± 0.11** (81/16) | 10.83 ± 0.29 (67/14) | 10.70 ± 0.21 (93/16) | 10.88 ± 0.25 (95/14) | 10.67 ± 0.18 (76/11) | 8.34 ± 0.79** (39/9)
7^d,e,h^ | 17.70 ± 0.28** (57/15) | 17.45 ± 0.52 (44/12) | 17.49 ± 0.48 (52/14) | 16.71 ± 0.44 (56/14) | 16.93 ± 0.39 (46/11) | 13.90 ± 1.17** (21/7)
10^d,e,h^ | 25.25 ± 0.42** (57/15) | 24.97 ± 0.60 (44/12) | 25.36 ± 0.54 (52/14) | 23.88 ± 0.49 (56/14) | 23.22 ± 0.40* (46/11) | 21.16 ± 0.87** (19/6)
13^d,e,h^ | 33.12 ± 0.50** (57/15) | 32.57 ± 0.59 (44/12) | 33.05 ± 0.56 (52/14) | 30.76 ± 0.48** (56/14) | 29.61 ± 0.46** (46/11) | 26.44 ± 1.13** (19/6)
16^d,e,h^ | 40.50 ± 0.59** (57/15) | 39.96 ± 0.70 (44/12) | 39.75 ± 0.65 (52/14) | 37.33 ± 0.56** (56/14) | 35.44 ± 0.67** (46/11) | 31.31 ± 1.15** (19/6)
19^d,e,h^ | 51.27 ± 0.68** (57/15) | 50.39 ± 1.33 (44/12) | 50.23 ± 0.98 (52/14) | 47.20 ± 0.88** (56/14) | 45.19 ± 0.69** (45/11) | 38.66 ± 1.38** (19/6)
21^d,e,h^ | 60.96 ± 0.61** (57/15) | 59.73 ± 1.43 (44/12) | 60.00 ± 1.03 (52/14) | 56.03 ± 0.92** (56/14) | 53.63 ± 0.86** (45/11) | 45.84 ± 1.64** (15/5)
25^d,e,h^ | 79.18 ± 0.85** (57/15) | 79.56 ± 1.58 (44/12) | 78.69 ± 1.38 (52/14) | 75.14 ± 1.03 (56/14) | 73.80 ± 0.99* (45/11) | 63.29 ± 2.27** (14/5)
28^d,e,h^ | 97.60 ± 1.28** (57/15) | 98.73 ± 1.98 (44/12) | 97.31 ± 1.72 (52/14) | 91.62 ± 1.34* (56/14) | 90.94 ± 1.16* (45/11) | 77.34 ± 3.18** (13/4)
Female
1 | 7.13 ± 0.09 (115/16) | 7.20 ± 0.14 (80/13) | 7.25 ± 0.08 (102/15) | 7.07 ± 0.11 (93/14) | 7.00 ± 0.14 (48/11) | 6.53 ± 0.33* (45/11)
4 | 10.18 ± 0.17** (115/16) | 10.20 ± 0.24 (80/13) | 10.37 ± 0.13 (102/15) | 10.39 ± 0.22 (92/14) | 10.18 ± 0.14 (46/11) | 8.37 ± 0.87** (37/8)
7 | 16.55 ± 0.33** (63/15) | 16.67 ± 0.41 (52/12) | 16.79 ± 0.39 (60/14) | 16.17 ± 0.38 (55/14) | 16.14 ± 0.30 (36/11) | 14.12 ± 0.71** (23/6)
10 | 23.72 ± 0.41** (63/15) | 24.01 ± 0.43 (52/12) | 24.53 ± 0.44 (59/14) | 23.35 ± 0.43 (55/14) | 21.92 ± 0.29* (36/11) | 20.23 ± 0.72** (23/6)
13 | 31.30 ± 0.53** (63/15) | 31.58 ± 0.39 (52/12) | 32.15 ± 0.49 (59/14) | 29.96 ± 0.50 (55/14) | 28.33 ± 0.33** (35/11) | 25.54 ± 0.94** (23/6)
16 | 38.24 ± 0.62** (63/15) | 38.51 ± 0.42 (52/12) | 38.47 ± 0.55 (59/14) | 36.30 ± 0.58 (55/14) | 34.18 ± 0.44** (35/11) | 30.33 ± 1.00** (23/6)
19 | 47.85 ± 0.77** (63/15) | 48.17 ± 0.83 (52/12) | 47.68 ± 0.83 (59/14) | 45.81 ± 0.84 (55/14) | 43.34 ± 0.62** (35/11) | 36.65 ± 1.77** (23/6)
21 | 56.34 ± 0.78** (63/15) | 56.17 ± 0.97 (52/12) | 56.59 ± 0.82 (59/14) | 54.05 ± 0.82 (55/14) | 50.35 ± 0.80** (35/11) | 45.51 ± 1.41** (17/5)
25 | 71.80 ± 0.63** (63/15) | 72.67 ± 1.24 (52/12) | 72.11 ± 0.97 (59/14) | 70.01 ± 0.93 (55/14) | 67.90 ± 0.91* (35/11) | 58.87 ± 3.62** (16/5)
28 | 85.99 ± 0.89** (63/15) | 87.68 ± 1.50 (52/12) | 87.47 ± 1.23 (59/14) | 83.91 ± 1.19 (55/14) | 82.38 ± 1.58 (35/11) | 66.99 ± 5.91** (12/4)
Male and Female
1 | 7.33 ± 0.08* (196/16) | 7.42 ± 0.16 (148/14) | 7.42 ± 0.09 (195/16) | 7.12 ± 0.14 (191/15) | 7.34 ± 0.13 (124/11) | 6.69 ± 0.28* (100/12)
4 | 10.52 ± 0.14** (196/16) | 10.57 ± 0.27 (147/14) | 10.49 ± 0.16 (195/16) | 10.62 ± 0.22 (187/14) | 10.47 ± 0.16 (122/11) | 8.20 ± 0.80** (76/9)
7 | 17.09 ± 0.28** (120/15) | 17.04 ± 0.44 (96/12) | 17.09 ± 0.41 (112/14) | 16.42 ± 0.39 (111/14) | 16.59 ± 0.35 (82/11) | 13.48 ± 1.14** (44/7)
10 | 24.45 ± 0.38** (120/15) | 24.47 ± 0.47 (96/12) | 24.87 ± 0.47 (111/14) | 23.59 ± 0.44 (111/14) | 22.67 ± 0.37* (82/11) | 20.61 ± 0.75** (42/6)
13 | 32.17 ± 0.49** (120/15) | 32.05 ± 0.44 (96/12) | 32.53 ± 0.49 (111/14) | 30.37 ± 0.45* (111/14) | 29.07 ± 0.40** (81/11) | 25.91 ± 0.99** (42/6)
16 | 39.33 ± 0.58** (120/15) | 39.19 ± 0.50 (96/12) | 39.02 ± 0.56 (111/14) | 36.82 ± 0.52** (111/14) | 34.93 ± 0.54** (81/11) | 30.78 ± 1.05** (42/6)
19 | 49.49 ± 0.65** (120/15) | 49.21 ± 1.03 (96/12) | 48.84 ± 0.84 (111/14) | 46.48 ± 0.79* (111/14) | 44.37 ± 0.65** (80/11) | 37.65 ± 1.45** (42/6)
21 | 58.55 ± 0.61** (120/15) | 57.80 ± 1.14 (96/12) | 58.11 ± 0.85 (111/14) | 55.01 ± 0.78* (111/14) | 52.23 ± 0.81** (80/11) | 45.57 ± 1.42** (32/5)
25 | 75.32 ± 0.54** (120/15) | 75.80 ± 1.32 (96/12) | 75.14 ± 1.08 (111/14) | 72.56 ± 0.86 (111/14) | 71.25 ± 0.94* (80/11) | 59.75 ± 3.22** (30/5)
28 | 91.54 ± 0.92** (120/15) | 92.78 ± 1.69 (96/12) | 92.06 ± 1.37 (111/14) | 87.76 ± 1.07 (111/14) | 87.02 ± 1.25 (80/11) | 73.24 ± 2.94** (25/4)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error (number of pups/number of litters). Body weight data are presented in grams.

^b^ Each exposed group was compared to the vehicle control group with the Williams test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunnett test when no trend was present.

^c^ Total pup weight on postnatal day (PND) 1 divided by number of live pups on PND 1.

^d^ Data are presented as mean of the litter means ± standard error (number of pups/number of litters). Body weight data are presented in grams.

^e^ Statistical analysis performed using mixed models with random litter effect for both trend and pairwise tests, using the Dunnett-Hsu adjustment for multiple comparisons.

^f^ PND 4 prestandardization.

^g^ Individual pup weights first adjusted for live litter size on PND 1.

^h^ Individual pup weights first adjusted for live litter size on PND 4 poststandardization.

#### Three-month Study (Postweaning Phase)

During the 3-month postweaning phase, one male and two females in the 500 mg/L group were euthanized moribund with clinical observations of ruffled coat, hunched, and lethargy (Appendix E). All other animals survived until scheduled removal. Male and female rats in exposed groups ≤250 mg/L had body weights within 10% of the respective control groups, with sporadic but significant decreases in males and increases in females compared to the control groups. Body weights of the 500 mg/L group were significantly decreased relative to those of the control group for males and females throughout the postweaning period. Terminal body weight at 500 mg/L was significantly decreased (by 27% for males and 11% for females) compared to that of control animals (Table 9, Table 10; Figure 1).

Table 9 Summary of Survival and Body Weights of Male Rats in the Perinatal and Three-month Drinking Water Study of Sodium Metavanadate

Postnatal Day | 0 mg/L | | 31.3 mg/L | | | 62.5 mg/L | | | 125 mg/L | | | 250 mg/L | | | 500 mg/L
Postnatal Day | Wt. (g)^a,b^ | n^c^ | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n
28^d^ | 96.9 ± 1.7** | 15 (12) | 99.3 ± 2.1 | 102.4 | 15 (11) | 98.4 ± 1.9 | 101.5 | 15 (12) | 92.5 ± 1.6 | 95.4 | 15 (11) | 92.2 ± 1.7 | 95.1 | 15 (10) | 79.0 ± 3.7** | 81.4 | 13 (4)
35 | 134.0 ± 2.3** | 15 (12) | 137.0 ± 2.6 | 102.2 | 15 (11) | 138.1 ± 2.9 | 103.1 | 15 (12) | 128.2 ± 1.9 | 95.7 | 15 (11) | 127.1 ± 2.5 | 94.9 | 15 (10) | 99.2 ± 4.6** | 74.0 | 12 (4)
42 | 181.9 ± 2.5** | 15 (12) | 183.6 ± 3.3 | 100.9 | 15 (11) | 186.5 ± 3.5 | 102.6 | 15 (12) | 174.1 ± 3.1 | 95.7 | 15 (11) | 169.6 ± 3.2 | 93.3 | 15 (10) | 131.7 ± 7.8** | 72.4 | 12 (4)
49 | 231.6 ± 3.4** | 15 (12) | 235.7 ± 3.7 | 101.8 | 15 (11) | 237.5 ± 4.3 | 102.5 | 15 (12) | 219.0 ± 3.4 | 94.6 | 15 (11) | 216.6 ± 3.8 | 93.5 | 15 (10) | 170.0 ± 12.4** | 73.4 | 12 (4)
56 | 280.2 ± 3.8** | 15 (12) | 283.7 ± 4.0 | 101.2 | 15 (11) | 283.4 ± 4.5 | 101.1 | 15 (12) | 261.8 ± 4.0* | 93.4 | 15 (11) | 259.4 ± 3.6* | 92.5 | 15 (10) | 208.1 ± 15.2** | 74.2 | 12 (4)
63 | 320.3 ± 4.5** | 15 (12) | 325.2 ± 3.9 | 101.5 | 15 (11) | 322.8 ± 6.6 | 100.8 | 15 (12) | 301.5 ± 4.7 | 94.1 | 15 (11) | 295.5 ± 4.5* | 92.2 | 15 (10) | 239.9 ± 17.3** | 74.9 | 12 (4)
70 | 353.6 ± 5.3** | 15 (12) | 353.4 ± 5.0 | 99.9 | 15 (11) | 353.7 ± 5.6 | 100.0 | 15 (12) | 328.6 ± 5.1* | 92.9 | 15 (11) | 321.6 ± 5.0** | 91.0 | 15 (10) | 265.4 ± 18.2** | 75.1 | 12 (4)
77 | 377.8 ± 6.0** | 15 (12) | 378.2 ± 5.8 | 100.1 | 15 (11) | 377.6 ± 5.8 | 100.0 | 15 (12) | 352.3 ± 5.1* | 93.3 | 15 (11) | 345.4 ± 5.9** | 91.4 | 15 (10) | 285.1 ± 18.0** | 75.5 | 12 (4)
84 | 397.8 ± 6.3** | 15 (12) | 399.0 ± 5.6 | 100.3 | 15 (11) | 402.0 ± 6.3 | 101.1 | 15 (12) | 370.2 ± 5.6* | 93.1 | 15 (11) | 364.4 ± 5.9** | 91.6 | 15 (10) | 301.2 ± 17.7** | 75.7 | 12 (4)
91 | 415.3 ± 6.3** | 15 (12) | 419.0 ± 6.0 | 100.9 | 15 (11) | 418.2 ± 6.1 | 100.7 | 15 (12) | 388.0 ± 5.8* | 93.4 | 15 (11) | 382.6 ± 7.2** | 92.1 | 15 (10) | 315.4 ± 16.3** | 75.9 | 12 (4)
98 | 427.2 ± 6.1** | 15 (12) | 429.2 ± 6.7 | 100.5 | 15 (11) | 424.2 ± 5.9 | 99.3 | 15 (12) | 398.5 ± 6.9* | 93.3 | 15 (11) | 392.0 ± 7.3** | 91.8 | 15 (10) | 322.0 ± 16.7** | 75.4 | 12 (4)
105 | 441.8 ± 6.1** | 15 (12) | 440.0 ± 6.9 | 99.6 | 15 (11) | 434.4 ± 6.9 | 98.3 | 15 (12) | 407.4 ± 7.0** | 92.2 | 15 (11) | 399.1 ± 7.7** | 90.3 | 15 (10) | 329.5 ± 18.5** | 74.6 | 12 (4)
112 | 453.0 ± 6.6** | 15 (12) | 449.6 ± 7.4 | 99.2 | 15 (11) | 449.2 ± 7.0 | 99.2 | 15 (12) | 416.5 ± 7.4** | 91.9 | 15 (11) | 407.3 ± 7.9** | 89.9 | 15 (10) | 338.4 ± 16.9** | 74.7 | 12 (4)
119^e,f^ | 459.1 ± 7.4** | 10^f^ | 452.9 ± 9.0 | 98.6 | 10 | 460.7 ± 8.0 | 100.4 | 10 | 424.1 ± 10.1* | 92.4 | 10 | 413.3 ± 9.2** | 90.0 | 10 | 335.3 ± 10.0** | 73.0 | 12

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Statistical analysis performed using mixed models with random litter effect for both trend and pairwise tests, using the Dunnett-Hsu adjustment for multiple comparisons.

^b^ Weights shown are mean of the litter means ± standard error.

^c^ Number of individual animals (number of litters); includes F_1_ core and investigative study animals.

^d^ Postnatal day (PND) 28 is the day animals were placed on study after pups were weaned.

^e^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^f^ Number of individual animals includes only the F_1_ core animals. Investigative study animals were removed on PND 116 (females) and PND 117 (males).

Table 10 Summary of Survival and Body Weights of Female Rats in the Perinatal and Three-month Drinking Water Study of Sodium Metavanadate

Postnatal Day | 0 mg/L | | 31.3 mg/L | | | 62.5 mg/L | | | 125 mg/L | | | 250 mg/L | | | 500 mg/L
Postnatal Day | Wt. (g)^a,b^ | n^c^ | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n
28^d^ | 85.3 ± 1.3** | 15 (12) | 89.7 ± 1.4 | 105.2 | 15 (11) | 88.3 ± 1.1 | 103.6 | 15 (12) | 83.1 ± 1.6 | 97.4 | 15 (11) | 84.4 ± 1.2 | 99.0 | 15 (10) | 66.1 ± 6.6** | 77.5 | 12 (4)
35 | 109.8 ± 3.7** | 15 (12) | 114.9 ± 2.1 | 104.6 | 15 (11) | 116.9 ± 1.7 | 106.4 | 15 (12) | 110.4 ± 2.6 | 100.6 | 15 (11) | 109.4 ± 1.7 | 99.7 | 15 (10) | 88.2 ± 3.6** | 80.4 | 11 (3)
42 | 143.8 ± 2.4** | 15 (12) | 148.1 ± 2.8 | 103.0 | 15 (11) | 147.7 ± 2.2 | 102.7 | 15 (12) | 142.6 ± 3.3 | 99.1 | 15 (11) | 139.5 ± 2.6 | 97.0 | 15 (10) | 105.7 ± 7.6** | 73.5 | 11 (3)
49 | 170.4 ± 2.4** | 15 (12) | 174.9 ± 3.0 | 102.6 | 15 (11) | 171.3 ± 2.1 | 100.5 | 15 (12) | 167.5 ± 3.4 | 98.3 | 15 (11) | 166.3 ± 3.0 | 97.6 | 15 (10) | 132.6 ± 5.2** | 77.8 | 10 (3)
56 | 191.6 ± 2.5** | 15 (12) | 199.1 ± 3.1 | 103.9 | 15 (11) | 193.7 ± 2.4 | 101.1 | 15 (12) | 190.5 ± 4.5 | 99.4 | 15 (11) | 189.9 ± 2.9 | 99.1 | 15 (10) | 156.2 ± 5.3** | 81.5 | 10 (3)
63 | 208.5 ± 2.6** | 15 (12) | 218.6 ± 3.8 | 104.8 | 15 (11) | 210.4 ± 2.6 | 100.9 | 15 (12) | 206.6 ± 4.9 | 99.1 | 15 (11) | 211.2 ± 3.4 | 101.3 | 15 (10) | 177.7 ± 3.6** | 85.2 | 10 (3)
70 | 219.7 ± 4.0** | 15 (12) | 233.9 ± 4.4* | 106.5 | 15 (11) | 225.6 ± 3.2 | 102.7 | 15 (12) | 219.6 ± 5.5 | 100.0 | 15 (11) | 225.4 ± 3.5 | 102.6 | 15 (10) | 190.7 ± 2.6** | 86.8 | 10 (3)
77 | 229.4 ± 3.6** | 15 (12) | 248.8 ± 4.0* | 108.5 | 14 (10)^e^ | 233.7 ± 3.3 | 101.9 | 15 (12) | 229.1 ± 6.0 | 99.8 | 15 (11) | 237.4 ± 3.2 | 103.5 | 15 (10) | 202.8 ± 2.4** | 88.4 | 10 (3)
84 | 238.1 ± 3.7** | 15 (12) | 257.7 ± 5.1* | 108.3 | 15 (11) | 241.3 ± 3.6 | 101.3 | 15 (12) | 239.5 ± 6.7 | 100.6 | 15 (11) | 244.1 ± 3.3 | 102.5 | 15 (10) | 208.3 ± 1.6** | 87.5 | 10 (3)
91 | 244.7 ± 3.6* | 15 (12) | 267.1 ± 4.0** | 109.2 | 15 (11) | 254.2 ± 4.5 | 103.9 | 15 (12) | 250.2 ± 6.6 | 102.2 | 15 (11) | 258.2 ± 3.5 | 105.5 | 15 (10) | 222.6 ± 2.4* | 91.0 | 10 (3)
98 | 251.7 ± 3.3** | 15 (12) | 267.8 ± 3.2* | 106.4 | 14 (11)^e^ | 253.4 ± 3.4 | 100.7 | 15 (12) | 251.0 ± 6.3 | 99.7 | 15 (11) | 259.0 ± 3.7 | 102.9 | 15 (10) | 223.2 ± 2.4** | 88.7 | 10 (3)
105 | 256.5 ± 3.7** | 15 (12) | 275.8 ± 4.5* | 107.5 | 15 (11) | 257.0 ± 4.4 | 100.2 | 15 (12) | 256.1 ± 6.7 | 99.9 | 15 (11) | 261.6 ± 3.3 | 102.0 | 15 (10) | 225.6 ± 2.3** | 87.9 | 10 (3)
112 | 261.5 ± 3.0** | 15 (12) | 279.2 ± 5.3* | 106.8 | 15 (11) | 263.3 ± 3.8 | 100.7 | 15 (12) | 259.6 ± 6.5 | 99.3 | 15 (11) | 266.2 ± 3.2 | 101.8 | 15 (10) | 230.4 ± 2.8** | 88.1 | 10 (3)
119^f,g^ | 265.7 ± 1.9** | 10^g^ | 282.7 ± 5.7 | 106.4 | 10 | 267.5 ± 4.9 | 100.7 | 10 | 266.7 ± 8.7 | 100.4 | 10 | 272.5 ± 4.6 | 102.6 | 10 | 235.1 ± 3.1** | 88.5 | 10

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Statistical analysis performed using mixed models with random litter effect for both trend and pairwise tests, using the Dunnett-Hsu adjustment for multiple comparisons.

^b^ Weights shown are mean of the litter means ± standard error.

^c^ Number of individual animals (number of litters); includes F_1_ core and investigative study animals.

^d^ Postnatal day (PND) 28 is the day animals were placed on study after pups were weaned.

^e^ One F_1_ core female PND 77 body weight from the 31.3 mg/L group and one F_1_ investigative study female PND 98 body weight from the 31.3 mg/L group were excluded as outliers.

^f^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^g^ Number of individual animals includes only the F_1_ core animals. Investigative study animals were removed on PND 116 (females) and PND 117 (males).

Figure 1

Growth Curves for Male and Female Rats in the Perinatal and Three-month Drinking Water Study of Sodium Metavanadate

Growth curves are shown for (A) males and (B) females.

Water consumption continued to be lower in a concentration-related fashion throughout the postweaning period (PND 28–112). Water consumption over the PND 28–112 interval by males exposed to 250 and 500 mg/L was significantly decreased by 11% and 16%, respectively, compared to that of the control group (Table 11). Water consumption by exposed females was lower in comparison to the control group over the PND 28–112 interval, with a significant decrease of 19% and 28% at 250 and 500 mg/L, respectively. For both males and females, consumption at concentrations ≤125 mg/L was similar to that of the control groups throughout the postweaning period. Sodium metavanadate intake during the 3-month postweaning phase (PND 28–112) is presented in Table 11. Due to reduced water consumption over the course of the study, sodium metavanadate intake was less than dose-proportional (12- to 13-fold increase in intake by males and females versus 16-fold increase in drinking water concentration for the 31.3 mg/L to 500 mg/L groups).

Table 11 Summary of Water and Sodium Metavanadate Consumption by Male and Female Rats in the Perinatal and Three-month Drinking Water Study

Postnatal Day^a^ | 0 mg/L | 31.3 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L
Male (g/kg/day)^b^
28–35 | 147.0 ± 3.9* (8) | 146.2 ± 4.9 (9) | 161.0 ± 4.1 (7) | 159.1 ± 7.6 (9) | 143.3 ± 2.6 (8) | 111.5 ± 6.1* (7)
49–56 | 121.6 ± 3.1** (8) | 128.0 ± 2.7 (9) | 122.0 ± 4.3 (8) | 122.4 ± 4.7 (9) | 109.4 ± 3.2* (8) | 101.7 ± 2.6** (7)
70–77 | 79.9 ± 2.5** (8) | 80.0 ± 1.2 (9) | 78.0 ± 2.0 (8) | 80.5 ± 2.7 (9) | 71.7 ± 2.4 (8) | 71.8 ± 2.5 (7)
105–112 | 57.2 ± 2.1** (8) | 62.3 ± 1.4 (9) | 59.4 ± 1.6 (8) | 55.6 ± 1.5 (9) | 49.5 ± 1.2 (8) | 47.8 ± 1.3* (7)
28–112 | 86.4 ± 2.1** (8) | 89.3 ± 1.3 (9) | 88.2 ± 1.5 (8) | 87.1 ± 2.6 (9) | 76.9 ± 1.8* (8) | 72.4 ± 1.3** (7)
Chemical Intake (mg/kg/day)^c,d^
28–112 | 0.0 ± 0.0 (8) | 2.8 ± 0.0 (9) | 5.5 ± 0.1 (8) | 10.9 ± 0.3 (9) | 19.2 ± 0.5 (8) | 36.2 ± 0.6 (7)
Female (g/kg/day)
28–35 | 133.9 ± 14.8 (5) | 151.2 ± 13.8 (6) | 151.7 ± 4.4 (5) | 149.8 ± 7.3 (8) | 142.2 ± 2.5 (5) | 119.5 ± 8.5 (4)
49–56 | 126.8 ± 3.2** (5) | 120.7 ± 10.6 (6) | 123.3 ± 6.4 (5) | 118.6 ± 1.5 (8) | 106.3 ± 3.3** (5) | 101.6 ± 7.2** (4)
70–77 | 94.8 ± 3.7** (5) | 92.3 ± 7.9 (6) | 95.7 ± 3.7 (5) | 92.8 ± 2.9 (8) | 79.2 ± 3.3* (5) | 72.6 ± 4.9* (4)
105–112 | 85.6 ± 5.9** (5) | 78.8 ± 5.2 (6) | 78.4 ± 2.7 (5) | 79.6 ± 2.4 (8) | 61.3 ± 3.1** (5) | 54.7 ± 3.3** (4)
28–112 | 105.5 ± 1.6** (5) | 101.3 ± 7.2 (6) | 103.5 ± 3.3 (5) | 101.7 ± 2.3 (8) | 85.4 ± 3.4** (5) | 75.8 ± 4.4** (4)
Chemical Intake (mg/kg/day)
28–112 | 0.0 ± 0.0 (5) | 3.2 ± 0.2 (6) | 6.5 ± 0.2 (5) | 12.7 ± 0.3 (8) | 21.4 ± 0.9 (5) | 37.9 ± 2.2 (4)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error (number of cages).

^b^ Each exposed group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^c^ Chemical intake calculated as: ([exposure concentration × water consumption]/[average body weight of day range]).

^d^ No statistical analysis was performed on the chemical intake data.

Exposure to sodium metavanadate did not affect the time to balanopreputial separation (BPS) attainment (Appendix E). Vaginal opening (VO) was significantly delayed by 3.2 days in the 250 mg/L group (Table 12). The significant delay was also observed when adjusted for body weight on day of attainment. Furthermore, body weight at attainment in the 250 mg/L group was significantly increased relative to the control group. Pubertal markers were not evaluated at 500 mg/L due to the magnitude of body weight effects; therefore, 250 mg/L was the highest exposure concentration available for VO analysis.

Table 12 Summary of Vaginal Opening of F_1_ Female Rats Exposed to Sodium Metavanadate in the Perinatal and Three-month Drinking Water Study

Parameter^a^ | 0 mg/L | 31.3 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L
No. Examined^b^ | 15 (12) | 15 (11) | 15 (12) | 15 (11) | 15 (10)
No. Not Attaining^c^ | 1 (1) | 0 (0) | 0 (0) | 0 (0) | 0 (0)
Day of VO
Litter mean^d,e^ | 36.8 ± 0.9** | 38.1 ± 0.9 | 37.0 ± 0.5 | 37.7 ± 0.7 | 40.0 ± 0.6**
Adjusted litter mean^d,f,g^ | 36.7 ± 0.9** | 38.4 ± 0.9 | 37.2 ± 0.5 | 37.4 ± 0.7 | 39.9 ± 0.6**
Body Weight at Attainment (g)^h^ | 120.2 ± 3.9 | 127.3 ± 3.3 | 124.7 ± 2.7 | 122.0 ± 4.1 | 129.8 ± 3.0*
Body Weight at Weaning (g)^h^ | 85.3 ± 1.2* | 89.3 ± 1.5 | 88.6 ± 1.1 | 82.8 ± 1.5 | 84.6 ± 1.3

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

VO = vaginal opening.

^a^ Data are displayed as mean ± standard error unless otherwise noted; values are based on litter means, not individual pup values.

^b^ No. Examined = the number of pups examined (number of litters).

^c^ No. Not Attaining = number of pups (number of litters) that survived to the end of the observation period without attaining VO.

^d^ Summary statistics and mixed model results are presented for animals that attained during the observation period.

^e^ Statistical analysis performed using mixed effects models with exposure concentration as a covariate, litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^f^ Statistical analysis performed using mixed effects models with exposure concentration and weaning weight as covariates, litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^g^ Adjusted based on body weight at weaning.

^h^ Analysis of body weight at attainment and body weight at weaning for both linear trend and pairwise comparisons were performed using mixed effects models with exposure concentration as a covariate, litter as a random effect, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

Several significant organ weight changes were observed but were considered related to reduced growth and not toxicologically relevant (Appendix E).

At study termination, erythrocyte count was significantly increased in the ≥125 mg/L male rats and in the 250 mg/L female rats (Table 13). Compared to the control groups, erythrocyte count was approximately 5% higher in the 250 mg/L male and female rats and 7% higher in the 500 mg/L male rats, indicating erythrocytosis. In male rats, the mean cell volume (MCV) was significantly decreased in the ≥125 mg/L groups, whereas in female rats, the MCV was significantly decreased in the 500 mg/L group. Compared to the control groups, MCV was approximately 7% and 4% lower in the 500 mg/L male and female rats, respectively. The decreases in MCV indicated an erythrocyte microcytosis. Additionally, in male rats, the mean cell hemoglobin (MCH) and mean cell hemoglobin concentration (MCHC) were significantly decreased in the ≥125 mg/L and 500 mg/L groups, respectively. In female rats, the MCH and MCHC were significantly decreased in the ≥250 mg/L and 500 mg/L groups, respectively. At PND 28, there were a number of low magnitude, statistically significant changes in male and/or female rats that were consistent with changes at study termination, demonstrating the beginning of an exposure-related progressive microcytic erythrocytosis (Appendix E).

Table 13 Summary of Select Hematology Data for Male and Female Rats in the Perinatal and Three-month Drinking Water Study of Sodium Metavanadate

Endpoint^a,b^ | 0 mg/L | 31.3 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L
Male
n | 10 | 9 | 10 | 9 | 10 | 12^c^
Hematocrit (%) | 47.3 ± 0.6 | 47.8 ± 0.7 | 46.7 ± 0.7 | 47.2 ± 0.8 | 47.7 ± 0.5 | 47.0 ± 0.8
Hemoglobin (g/dL) | 15.0 ± 0.1* | 15.2 ± 0.2 | 15.0 ± 0.2 | 14.8 ± 0.2 | 15.0 ± 0.1 | 14.5 ± 0.2
Erythrocytes (10^6^/µL) | 8.61 ± 0.09** | 8.75 ± 0.12 | 8.75 ± 0.08 | 8.96 ± 0.09* | 9.04 ± 0.09** | 9.23 ± 0.18**
Mean Cell Volume (fL) | 54.9 ± 0.5** | 54.7 ± 0.5 | 53.4 ± 0.5 | 52.7 ± 0.7* | 52.8 ± 0.3** | 51.0 ± 0.4**
Mean Cell Hemoglobin (pg) | 17.4 ± 0.1** | 17.4 ± 0.1 | 17.1 ± 0.1 | 16.6 ± 0.2** | 16.6 ± 0.1** | 15.8 ± 0.1**
Mean Cell Hemoglobin Concentration (g/dL) | 31.7 ± 0.2** | 31.7 ± 0.2 | 32.0 ± 0.2 | 31.4 ± 0.1 | 31.4 ± 0.1 | 30.9 ± 0.1**
Female
n | 10 | 10 | 9 | 9 | 8 | 10^c^
Hematocrit (%) | 44.1 ± 0.8 | 45.0 ± 0.4 | 42.8 ± 0.8 | 43.4 ± 0.5 | 45.6 ± 0.5 | 43.3 ± 0.6
Hemoglobin (g/dL) | 14.2 ± 0.2 | 14.5 ± 0.1 | 13.7 ± 0.4 | 14.1 ± 0.1 | 14.4 ± 0.1 | 13.6 ± 0.2
Erythrocytes (10^6^/µL) | 7.78 ± 0.10 | 8.02 ± 0.06 | 7.77 ± 0.16 | 7.96 ± 0.13 | 8.18 ± 0.10* | 7.97 ± 0.10
Mean Cell Volume (fL) | 56.7 ± 0.5** | 56.2 ± 0.5 | 55.2 ± 0.5 | 54.7 ± 0.7 | 55.8 ± 0.5 | 54.3 ± 0.4**
Mean Cell Hemoglobin (pg) | 18.2 ± 0.1** | 18.1 ± 0.2 | 17.7 ± 0.3 | 17.7 ± 0.3 | 17.6 ± 0.1* | 17.0 ± 0.1**
Mean Cell Hemoglobin Concentration (g/dL) | 32.2 ± 0.2** | 32.3 ± 0.2 | 32.0 ± 0.4 | 32.4 ± 0.2 | 31.6 ± 0.2 | 31.4 ± 0.2*

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ Group contained multiple animals per litter.

Urea nitrogen was significantly increased in both the ≥125 mg/L male groups and in the ≥250 mg/L female groups (Table 14). These changes were mild and consistent with dehydration and supported by higher urine specific gravity in the respective exposed groups (Appendix E). In both male and female rats, globulin concentrations were significantly decreased resulting in a significant increase in the albumin to globulin (A/G) ratio; these changes were observed in the ≥250 mg/L male groups and in the 500 mg/L female group. Compared to the control groups, globulin concentrations were approximately 19% and 14% lower in the 500 mg/L male and female rats, respectively. Cholesterol concentrations were significantly decreased in the ≥125 mg/L male groups and the ≥250 mg/L female groups. The alkaline phosphatase activity was mildly but significantly decreased in both the ≥250 mg/L male groups and in the ≥125 mg/L female groups. Alanine aminotransferase activity was mildly but significantly increased in the ≥125 mg/L female groups.

Table 14 Summary of Select Clinical Chemistry Data for Male and Female Rats in the Perinatal and Three-month Drinking Water Study of Sodium Metavanadate

Endpoint^a,b^ | 0 mg/L | 31.3 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L^c^
Male
n | 10 | 10 | 10 | 10 | 10 | 12
Urea Nitrogen (mg/dL) | 16.0 ± 0.4**^d^ | 15.4 ± 0.5 | 17.1 ± 0.7^d^ | 18.1 ± 0.8*^e^ | 23.0 ± 0.8**^e^ | 30.9 ± 1.0**^f^
Albumin (g/dL) | 4.61 ± 0.08* | 4.55 ± 0.03 | 4.44 ± 0.04 | 4.57 ± 0.10 | 4.71 ± 0.05 | 4.77 ± 0.07
Globulin (g/dL) | 2.50 ± 0.08**^d^ | 2.27 ± 0.04 | 2.37 ± 0.08^d^ | 2.39 ± 0.09^e^ | 2.19 ± 0.07**^d^ | 2.03 ± 0.03**^f^
A/G Ratio | 1.84 ± 0.06**^d^ | 2.01 ± 0.04 | 1.89 ± 0.08^d^ | 1.94 ± 0.04^e^ | 2.16 ± 0.07**^d^ | 2.36 ± 0.03**^f^
Cholesterol (mg/dL) | 141.6 ± 5.6**^e^ | 134.4 ± 3.7 | 132.8 ± 5.0^d^ | 125.2 ± 4.7* | 125.1 ± 7.0* | 111.6 ± 2.8**^g^
Alkaline Phosphatase (IU/L) | 128.9 ± 5.1**^d^ | 121.7 ± 5.1 | 128.8 ± 7.8^d^ | 123.7 ± 6.7 | 99.8 ± 5.8** | 96.9 ± 4.0**^h^
Female
n | 10 | 10 | 10 | 10 | 10 | 10
Urea Nitrogen (mg/dL) | 15.7 ± 0.7** | 15.5 ± 0.3 | 17.8 ± 0.9 | 16.6 ± 0.7 | 20.1 ± 0.7** | 26.2 ± 0.7**
Albumin (g/dL) | 4.86 ± 0.05 | 4.89 ± 0.07 | 4.92 ± 0.06 | 4.69 ± 0.07 | 4.94 ± 0.06 | 4.77 ± 0.06
Globulin (g/dL) | 1.90 ± 0.04** | 1.86 ± 0.06 | 1.82 ± 0.06 | 1.87 ± 0.06 | 1.78 ± 0.05 | 1.63 ± 0.05**
A/G Ratio | 2.57 ± 0.04** | 2.66 ± 0.11 | 2.74 ± 0.13 | 2.53 ± 0.09 | 2.80 ± 0.10 | 2.94 ± 0.08**
Cholesterol (mg/dL) | 119.1 ± 4.0** | 116.5 ± 3.2 | 127.3 ± 4.9 | 114.1 ± 5.1 | 108.3 ± 2.3* | 96.1 ± 2.9**
Alkaline Phosphatase (IU/L) | 112.2 ± 3.2** | 103.1 ± 6.3 | 106.8 ± 9.4 | 87.5 ± 5.1** | 74.8 ± 4.8** | 82.0 ± 4.1**
Alanine Aminotransferase (IU/L) | 41.0 ± 2.4** | 47.4 ± 2.7 | 45.1 ± 2.3 | 51.5 ± 3.2* | 50.4 ± 1.7** | 57.4 ± 3.2**

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ Group contained multiple animals per litter. Litter-based methods were not used in the analysis.

^d^ n = 9. One sample in the indicated group was excluded from analysis due to biological implausibility.

^e^ n = 8. Two samples in the indicated group were excluded from analysis due to biological implausibility.

^f^ n = 9. Three samples in the indicated group were excluded from analysis due to biological implausibility.

^g^ n = 10. Two samples in the indicated group were excluded from analysis due to biological implausibility.

^h^ n = 11. One sample in the indicated group was excluded from analysis due to biological implausibility.

Rats exposed to 500 mg/L sodium metavanadate displayed a small (10%) yet significant decrease in cauda epididymal weight (Appendix E). However, there were no correlating histopathological findings in either the testes or epididymides. Analysis of female vaginal cytology (0, 125, and 250 mg/L groups) indicated that sodium metavanadate did not affect the number of estrous cycles or overall estrous cycle length (Appendix E). Although the Markov model estimates of stage length indicated that the length of proestrus was slightly but significantly decreased in the 500 mg/L group, this was likely a spurious response given that the length of time in proestrus was lowest in 125 mg/L group and the length of time in the control group was longer than usually observed in higher powered NTP studies.^71,72^

##### Histopathology

This section describes the statistically significant or biologically noteworthy changes in the incidence of gross lesions and nonneoplastic lesions in the small and large intestines.

Small and large intestines: Histopathologically, significantly increased incidences of epithelial hyperplasia were observed in the epithelium of the small (ileum, jejunum, and duodenum) intestine, and higher incidences were observed in the large (cecum, colon, and rectum) intestine (Table 15). This lesion was most prevalent in the ileum, and the next highest incidences were seen in the jejunum. In both of these segments of the small intestine in male rats, this lesion was seen in animals exposed to ≥125 mg/L, with a significant trend and pairwise comparisons in the ileum of males exposed to ≥125 mg/L and in the jejunum of males exposed to ≥250 mg/L. Epithelial hyperplasia was seen in the duodenum of only one male in the 500 mg/L group. The severity of epithelial hyperplasia in the small intestine was generally minimal to mild and increased slightly with exposure concentration. Severities were similar in female rats; however, epithelial hyperplasia was not seen in the jejunum in the 250 mg/L female group and did not occur in the duodenum of female rats. Epithelial hyperplasia was observed in the ileum of females exposed to ≥125 mg/L, with a positive trend and significant increases in the ≥250 mg/L groups. In the jejunum, epithelial hyperplasia was observed in only one female exposed to 125 mg/L; a positive trend and a significant increase were observed in females exposed to 500 mg/L.

Table 15 Incidences of Epithelial Hyperplasia of the Large and Small Intestines in Male and Female Rats in the Perinatal and Three-month Drinking Water Study of Sodium Metavanadate

| 0 mg/L | 31.3 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L^a^
Male
n^b^ | 10 | 10 | 10^c^ | 10^c^ | 10^d^ | 13
Intestine, Small, Ileum
Epithelium, hyperplasia^e^ | 0** | 0 | 0 | 5* (1.4)^f^ | 9** (1.3) | 12** (2.1)
Intestine, Small, Jejunum
Epithelium, hyperplasia | 0** | –^g^ | 0 | 1 (1.0) | 6** (1.0) | 7** (1.4)
Intestine, Small, Duodenum
Epithelium, hyperplasia | 0 | – | – | – | 0 | 1 (1.0)
Intestine, Large, Cecum
Epithelium, hyperplasia | 0 | 0 | 0 | 0 | 2 (1.0) | 1 (2.0)
Intestine, Large, Rectum
Epithelium, hyperplasia | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Intestine, Any Site
Epithelium, hyperplasia | 0** | 0 | 0 | 5* | 9** | 13**
Female
n | 10^h^ | 0 | 10 | 10 | 10 | 12
Intestine, Small, Ileum
Epithelium, hyperplasia | 0** | – | 0 | 4 (1.3) | 9** (1.6) | 12** (2.1)
Intestine, Small, Jejunum
Epithelium, hyperplasia | 0** | – | – | 1 (1.0) | 0 | 6* (1.3)
Intestine, Large, Cecum
Epithelium, hyperplasia | 0 | – | – | 0 | 0 | 2 (2.0)
Intestine, Large, Rectum
Epithelium, hyperplasia | 0 | – | – | 0 | 0 | 1 (2.0)
Intestine, Large, Colon
Epithelium, hyperplasia | 0 | – | – | 0 | 0 | 2 (2.0)
Intestine, Any Site
Epithelium, hyperplasia | 0** | – | 0 | 4* | 9** | 12**

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Group contained multiple animals per litter. Litter-based methods were not used in the analysis.

^b^ Number of animals examined microscopically.

^c^ For the small intestine, ileum data, n = 9 for the male 62.5 and 125 mg/L groups.

^d^ For the large intestine, rectum data, n = 9 for the male 250 mg/L group.

^e^ Number of animals with lesion. Statistical analyses performed by Cochran-Armitage (trend) and Fisher’s exact (pairwise) one-sided tests.

^f^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

^g^ Data were not collected for an exposed group when animals exposed to higher concentrations exhibited no incidences of nonneoplastic lesions in that tissue.

^h^ For the small intestine, ileum data, n = 9 for the 0 mg/L female group.

Epithelial hyperplasia in the small intestine was characterized by elongated crypts and shortened villi. Crypts were lined by crowded epithelial cells with basophilic cytoplasm and elongated nuclei. There was also a paucity of Paneth cells and eosinophilic granules at the base. Villi had increased numbers of basophilic epithelial cells that formed multiple layers of epithelial cells and irregular fronds and blebs extending into the lumen (Figure 2).

Figure 2

Representative Images of Control Epithelium and Epithelial Hyperplasia of the Intestines of Rodents in the Three-month Drinking Water Studies of Sodium Metavanadate and Vanadyl Sulfate (H&E)

(A) Morphology of the epithelium of the ileum in a male control mouse. (B) Moderate epithelial hyperplasia in the ileum of a male mouse exposed to 335 mg/L vanadyl sulfate. (C) Marked epithelial hyperplasia in the ileum of a female mouse exposed to 335 mg/L vanadyl sulfate. H&E = hematoxylin and eosin stain.

The only exposure-related gross lesion observed was mucoid contents in the cecum of one male rat that was euthanized moribund (Appendix E).

Epithelial hyperplasia of the cecum was seen in the 250 and 500 mg/L male groups and in the rectum of one male in the 500 mg/L group (Table 15). The severity of this lesion was generally minimal to mild and increased slightly with exposure concentration. A male rat that was euthanized moribund also had minimal necrosis in the cecum, which correlated with the mucoid contents gross lesion. Severities of epithelial hyperplasia in the large intestine of females were similar to those of males; however, epithelial hyperplasia was seen only in the 500 mg/L group, in the cecum, rectum, and colon.

Microscopic findings in the large intestine consisted of elongated crypts lined by basophilic epithelial cells with an irregular luminal surface characterized by increased numbers of basophilic epithelial cells that occasionally formed multiple layers of epithelial cells and/or irregular fronds and blebs extending into the lumen. In the colon, the surface had a wavy appearance due to the elongation of some of the hyperplastic crypts.

Incidences of epithelial hyperplasia at all intestinal sites (combined) were observed in males and females exposed to ≥125 mg/L, with a significant trend and pairwise comparisons. The lesion occurred in the ileum of all 500 mg/L animals, except for one male. Epithelial hyperplasia was not observed in males or females exposed to ≤62.5 mg/L.

### Mice

#### Three-month Study

There was no effect on survival of male or female mice due to sodium metavanadate exposure. One 500 mg/L male mouse was removed from the study during week 3 due to clinical observations of ruffled coat, lethargy, hunched, and cold to touch, although it is unclear whether these can be fully attributed to sodium metavanadate exposure (Appendix E). One female 250 mg/L mouse was removed in week 5 due to a broken hind limb. Body weights of male mice in the 250 and 500 mg/L groups were significantly decreased relative to the control group for most of the study (Table 16; Figure 3). Although significant, the body weight of the 250 mg/L group was within 11% of that of the control group throughout the study. Terminal body weight of the 500 mg/L male group was 26% lower than that of the control group; mice in this group lost an average of 6% body weight in the first 3 weeks of the study and then continually gained weight for the remaining duration. Similarly, female mice in the 500 mg/L group had significantly decreased body weights at every interval after study day 0, with a terminal body weight 23% lower than that of the control group (Table 17; Figure 3). The 250 mg/L female body weight was 14% lower than that of the control group at study termination but was generally similar to the control group throughout. No body weight changes were seen in males or females exposed to ≤125 mg/L sodium metavanadate.

Table 16 Summary of Survival and Body Weights of Male Mice in the Three-month Drinking Water Study of Sodium Metavanadate

Study Day^a^ | | 0 mg/L | | 31.3 mg/L | | | 62.5 mg/L | | | 125 mg/L | | | 250 mg/L | | | 500 mg/L
Study Day^a^ | | Wt. (g)^b,c^ | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n
0 | | 23.0 ± 0.4 | 10 | 23.3 ± 0.3 | 101.4 | 10 | 23.2 ± 0.3 | 101.2 | 10 | 23.2 ± 0.4 | 101.2 | 10 | 23.4 ± 0.2 | 102.0 | 10 | 23.4 ± 0.2 | 101.9 | 10
7 | | 25.0 ± 0.3** | 10 | 25.2 ± 0.3 | 100.8 | 10 | 24.9 ± 0.3 | 99.6 | 10 | 25.1 ± 0.3 | 100.4 | 10 | 24.3 ± 0.3 | 97.0 | 10 | 21.9 ± 0.4** | 87.5 | 10
14 | | 26.2 ± 0.3** | 10 | 26.5 ± 0.3 | 101.1 | 10 | 26.0 ± 0.4 | 99.2 | 10 | 26.3 ± 0.4 | 100.2 | 10 | 25.4 ± 0.3 | 96.9 | 10 | 21.4 ± 0.7** | 81.6 | 9^d^
21 | | 27.8 ± 0.3** | 10 | 27.9 ± 0.4 | 100.1 | 10 | 27.3 ± 0.4 | 98.1 | 10 | 27.6 ± 0.5 | 99.4 | 10 | 26.2 ± 0.3** | 94.2 | 10 | 22.0 ± 0.6** | 79.1 | 9
28 | | 29.0 ± 0.4** | 10 | 29.4 ± 0.6 | 101.3 | 9^d^ | 28.5 ± 0.4 | 98.1 | 10 | 28.9 ± 0.5 | 99.4 | 10 | 27.0 ± 0.4** | 93.1 | 10 | 23.7 ± 0.5** | 81.6 | 9
35 | | 30.5 ± 0.5** | 10 | 30.7 ± 0.7 | 100.8 | 10 | 29.9 ± 0.4 | 97.9 | 10 | 30.5 ± 0.6 | 100.0 | 10 | 28.4 ± 0.5** | 93.0 | 10 | 24.9 ± 0.6** | 81.7 | 9
42 | | 32.2 ± 0.9** | 10 | 32.7 ± 0.7 | 101.6 | 10 | 31.7 ± 0.4 | 98.4 | 10 | 32.0 ± 0.7 | 99.6 | 10 | 29.6 ± 0.5* | 92.1 | 10 | 26.4 ± 0.5** | 82.3 | 9
49 | | 34.3 ± 0.7** | 10 | 34.5 ± 0.9 | 100.7 | 10 | 33.2 ± 0.5 | 96.8 | 10 | 33.8 ± 0.9 | 98.7 | 10 | 30.6 ± 0.5** | 89.3 | 10 | 27.2 ± 0.5** | 79.5 | 9
56 | | 35.0 ± 0.8** | 10 | 35.7 ± 0.9 | 102 | 10 | 34.3 ± 0.7 | 98.1 | 10 | 35.2 ± 1.0 | 100.6 | 10 | 31.5 ± 0.7** | 90.2 | 10 | 27.8 ± 0.6** | 79.4 | 9
63 | | 36.7 ± 1.0** | 10 | 37.5 ± 0.9 | 102.4 | 10 | 36.5 ± 0.7 | 99.6 | 10 | 37.3 ± 1.1 | 101.8 | 10 | 33.1 ± 0.6** | 90.2 | 10 | 28.9 ± 0.5** | 78.8 | 9
70 | | 37.6 ± 1.0** | 10 | 38.9 ± 1.1 | 103.2 | 10 | 37.2 ± 0.8 | 98.8 | 10 | 38.0 ± 1.0 | 100.9 | 10 | 34.1 ± 0.7** | 90.5 | 10 | 29.0 ± 0.5** | 77.1 | 9
77 | | 38.5 ± 1.1** | 10 | 39.9 ± 1.2 | 103.6 | 10 | 38.7 ± 0.9 | 100.4 | 10 | 39.3 ± 1.2 | 102.0 | 10 | 34.7 ± 0.7** | 90.1 | 10 | 29.3 ± 0.6** | 75.9 | 9
84 | 39.9 ± 1.2** | | 10 | 41.5 ± 1.3 | 104.0 | 10 | 40.1 ± 1.0 | 100.6 | 10 | 40.6 ± 1.2 | 101.7 | 10 | 35.8 ± 0.8** | 89.8 | 10 | 30.0 ± 0.6** | 75.2 | 9
91 | 41.9 ± 1.1** | | 10 | 43.3 ± 1.2 | 103.2 | 10 | 42.4 ± 1.1 | 101 | 10 | 42.7 ± 1.1 | 101.7 | 10 | 37.5 ± 0.9** | 89.5 | 10 | 31.2 ± 0.7** | 74.3 | 9

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Study day 0 is the day animals were placed on study.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Weights shown are mean ± standard error.

^d^ One animal weight was excluded as an outlier and thus excluded from analysis on the indicated study day.

Figure 3

Growth Curves for Male and Female Mice in the Three-month Drinking Water Study of Sodium Metavanadate

Growth curves are shown for (A) males and (B) females.

Table 17 Summary of Survival and Body Weights of Female Mice in the Three-month Drinking Water Study of Sodium Metavanadate

Study Day^a^ | 0 mg/L | | 31.3 mg/L | | | 62.5 mg/L | | | 125 mg/L | | | 250 mg/L | | | 500 mg/L
Study Day^a^ | Wt. (g)^b,c^ | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n
0 | 18.4 ± 0.3 | 10 | 18.4 ± 0.4 | 99.6 | 10 | 18.6 ± 0.3 | 101.1 | 10 | 18.6 ± 0.2 | 100.8 | 10 | 18.8 ± 0.3 | 102.0 | 10 | 18.7 ± 0.3 | 101.2 | 10
7 | 19.1 ± 0.4** | 10 | 19.0 ± 0.3 | 99.1 | 10 | 19.2 ± 0.2 | 100.3 | 10 | 18.5 ± 0.2 | 96.9 | 10 | 19.0 ± 0.2 | 99.1 | 10 | 17.7 ± 0.3** | 92.3 | 10
14 | 20.4 ± 0.4** | 10 | 20.9 ± 0.4 | 102.2 | 10 | 20.7 ± 0.4 | 101.4 | 10 | 20.2 ± 0.3 | 98.8 | 10 | 20.0 ± 0.2 | 97.8 | 10 | 19.0 ± 0.2** | 93.1 | 10
21 | 21.5 ± 0.3** | 10 | 21.6 ± 0.3 | 100.4 | 10 | 21.7 ± 0.4 | 100.9 | 10 | 21.5 ± 0.2 | 100 | 10 | 20.9 ± 0.3 | 97.1 | 10 | 20.3 ± 0.3* | 94.5 | 10
28 | 22.3 ± 0.5** | 9^d^ | 22.1 ± 0.5 | 99.2 | 10 | 22.3 ± 0.5 | 100.1 | 10 | 22.2 ± 0.4 | 99.7 | 10 | 21.6 ± 0.3 | 97.1 | 10 | 20.9 ± 0.2* | 93.9 | 10
35 | 23.5 ± 0.4** | 10 | 23.6 ± 0.5 | 100.2 | 10 | 24.3 ± 0.7 | 103.1 | 10 | 22.7 ± 0.4 | 96.3 | 10 | 22.6 ± 0.2 | 96.0 | 9 | 21.6 ± 0.3** | 91.6 | 10
42 | 24.2 ± 0.4** | 10 | 24.5 ± 0.6 | 101.5 | 10 | 25.3 ± 0.7 | 104.8 | 10 | 24.0 ± 0.4 | 99.3 | 10 | 23.2 ± 0.5 | 95.9 | 9 | 22.7 ± 0.3* | 93.8 | 10
49 | 25.2 ± 0.7** | 10 | 25.6 ± 0.6 | 101.4 | 10 | 27.1 ± 0.8 | 107.4 | 10 | 25.4 ± 0.6 | 100.5 | 10 | 24.6 ± 0.7 | 97.5 | 9 | 23.3 ± 0.2* | 92.2 | 10
56 | 25.8 ± 0.7** | 10 | 26.7 ± 0.8 | 103.5 | 10 | 28.2 ± 1.1 | 109.2 | 10 | 25.9 ± 0.8 | 100.4 | 10 | 24.7 ± 0.6 | 95.6 | 9 | 23.1 ± 0.2* | 89.4 | 10
63 | 27.3 ± 1.0** | 10 | 27.7 ± 0.8 | 101.5 | 10 | 29.6 ± 1.2 | 108.4 | 10 | 26.7 ± 1.0 | 97.7 | 10 | 25.4 ± 0.7 | 93.0 | 9 | 23.5 ± 0.3** | 86.2 | 10
70 | 29.2 ± 1.1** | 10 | 29.8 ± 0.9 | 102.2 | 10 | 31.1 ± 1.5 | 106.6 | 10 | 28.6 ± 0.8 | 97.9 | 10 | 25.9 ± 0.6* | 88.8 | 9 | 24.3 ± 0.2** | 83.3 | 10
77 | 29.3 ± 1.0** | 10 | 30.8 ± 0.8 | 105.1 | 10 | 32.1 ± 1.3 | 109.6 | 10 | 28.5 ± 0.9 | 97.4 | 10 | 26.7 ± 0.7 | 91.1 | 9 | 24.1 ± 0.2** | 82.2 | 10
84 | 30.8 ± 1.2** | 10 | 32.8 ± 1.0 | 106.5 | 10 | 33.0 ± 1.7 | 107.2 | 10 | 29.8 ± 1.0 | 96.9 | 10 | 26.7 ± 0.8* | 86.8 | 8^d^ | 24.5 ± 0.3** | 79.5 | 10
91 | 32.2 ± 1.2** | 10 | 33.9 ± 1.0 | 105.2 | 10 | 34.0 ± 1.6 | 105.6 | 10 | 30.9 ± 1.0 | 96.0 | 10 | 27.6 ± 0.9** | 85.7 | 9 | 24.9 ± 0.3** | 77.2 | 10

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Study day 0 is the day animals were placed on study.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Weights shown are mean ± standard error.

^d^ One animal weight was excluded as an outlier and thus excluded from analysis on the indicated study day.

In male and female mice, average water consumption during the 3-month study (study day 0–91) was 15% lower in the 500 mg/L groups than in the control groups; in all other exposed groups, it was within 5% of the control groups (Table 18). Sodium metavanadate intake over the course of the study (study day 0–91) is presented in Table 18.

Table 18 Summary of Water and Sodium Metavanadate Consumption by Male and Female Mice in the Three-month Drinking Water Study

Study Day^a^ | 0 mg/L | 31.3 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L
Male (g/kg/day)^b^
0–7 | 160.9 ± 7.2** (10) | 148.8 ± 3.2 (10) | 156.6 ± 4.5 (10) | 146.7 ± 4.5 (10) | 135.1 ± 4.4** (10) | 96.7 ± 3.3** (10)
21–28 | 150.6 ± 18.2 (10) | 121.5 ± 1.7 (8) | 136.2 ± 7.4 (10) | 122.2 ± 4.8 (8) | 134.4 ± 9.2 (10) | 116.1 ± 11.0 (8)
84–91 | 86.2 ± 4.0 (10) | 81.6 ± 3.0 (10) | 80.8 ± 3.6 (10) | 79.2 ± 3.8 (10) | 87.8 ± 3.0 (10) | 81.2 ± 2.6 (9)
0–91 | 110.2 ± 4.0** (10) | 105.6 ± 2.8 (10) | 107.7 ± 3.4 (10) | 104.7 ± 3.9 (10) | 106.6 ± 2.9 (10) | 93.2 ± 2.2** (9)
Chemical Intake (mg/kg/day)^c,d^
0–91 | 0.0 ± 0.0 (10) | 3.3 ± 0.1 (10) | 6.7 ± 0.2 (10) | 13.1 ± 0.5 (10) | 26.6 ± 0.7 (10) | 46.6 ± 1.1 (9)
Female (g/kg/day)
0–7 | 136.4 ± 2.9** (10) | 116.7 ± 3.5 (10) | 142.1 ± 2.2 (10) | 125.9 ± 1.2* (10) | 97.9 ± 1.1** (10) | 67.7 ± 1.2** (10)
21–28 | 128.5 ± 4.0** (10) | 107.8 ± 3.0 (10) | 131.1 ± 2.7 (10) | 122.1 ± 1.9 (10) | 111.3 ± 2.0** (10) | 91.6 ± 0.9** (10)
84–91 | 97.2 ± 5.6 (10) | 84.0 ± 2.5 (10) | 78.2 ± 3.7* (10) | 92.4 ± 2.7 (10) | 101.2 ± 3.3 (9) | 85.4 ± 2.2 (10)
0–91 | 107.8 ± 2.8** (10) | 103.2 ± 2.0 (10) | 107.9 ± 3.1 (10) | 108.3 ± 1.9 (10) | 103.8 ± 1.9 (9) | 91.2 ± 0.8** (10)
Chemical Intake (mg/kg/day)
0–91 | 0.0 ± 0.0 (10) | 3.2 ± 0.1 (10) | 6.7 ± 0.2 (10) | 13.5 ± 0.2 (10) | 25.9 ± 0.5 (9) | 45.6 ± 0.4 (10)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error (number of animals).

^b^ Each exposed group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^c^ Chemical intake calculated as: ([exposure concentration × water consumption]/[average body weight of day range]).

^d^ No statistical analysis was performed on the chemical intake data.

Absolute thymus weights were lower in the ≥62.5 mg/L male and ≥125 mg/L female groups compared to those of the control groups, although only the decreases in the ≥250 mg/L male groups and 500 mg/L female group were significant (Table 19). Relative thymus weights were lower in the ≥62.5 mg/L male groups, although none of these decreases were significant. Relative thymus weights were lower in the 62.5, 125, and 500 mg/L female groups, although none of these decreases were significant. These decreases were attributed to exposure to sodium metavanadate. Several other significant organ weight changes were considered secondary to body weight effects and not toxicologically relevant (Appendix E).

Table 19 Summary of Thymus Weights and Thymus-Weight-to-Body-Weight Ratios of Male and Female Mice in the Three-month Drinking Water Study of Sodium Metavanadate

Endpoint^a,b^ | 0 mg/L | 31.3 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L
Male
n | 10 | 10 | 10^c^ | 10 | 10 | 9
Terminal Body Wt. (g) | 41.9 ± 1.1** | 43.3 ± 1.2 | 42.4 ± 1.1 | 42.7 ± 1.1 | 37.5 ± 0.9** | 31.2 ± 0.7**
Thymus
Absolute (g) | 0.065 ± 0.007** | 0.071 ± 0.007 | 0.059 ± 0.005 | 0.059 ± 0.007 | 0.047 ± 0.003* | 0.042 ± 0.002**
Relative (mg/g)^d^ | 1.53 ± 0.12* | 1.65 ± 0.15 | 1.37 ± 0.09 | 1.37 ± 0.13 | 1.24 ± 0.07 | 1.34 ± 0.07
Female
n | 10 | 10 | 10 | 10 | 9 | 10
Terminal Body Wt. (g) | 32.2 ± 1.2** | 33.9 ± 1.0 | 34.0 ± 1.6 | 30.9 ± 1.0 | 27.6 ± 0.9** | 24.9 ± 0.3**
Thymus
Absolute (g) | 0.060 ± 0.003** | 0.069 ± 0.005 | 0.061 ± 0.003 | 0.053 ± 0.002 | 0.052 ± 0.003 | 0.045 ± 0.002**
Relative (mg/g) | 1.85 ± 0.07 | 2.02 ± 0.12 | 1.81 ± 0.07 | 1.71 ± 0.04 | 1.88 ± 0.07 | 1.79 ± 0.09

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ One animal’s thymus weight was excluded as an outlier and thus excluded from analysis.

^d^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

In both male and female mice, the erythrocyte count was significantly increased in the ≥125 mg/L groups, and the reticulocyte counts were significantly increased in the ≥250 mg/L male and female groups (Table 20). Compared to the control groups, erythrocyte counts were approximately 17% and 25% higher in the 500 mg/L male and female mice, respectively. In male mice, MCV was significantly decreased in all exposed groups, whereas in female mice MCV was significantly decreased in the ≥62.5 mg/L groups. Compared to the control groups, MCV was approximately 18% and 21% lower in the 500 mg/L male and female mice, respectively. The decreases in MCV indicated erythrocyte microcytosis. In contrast to the increased erythrocyte count, other markers of the erythron (hematocrit and hemoglobin) demonstrated decreases. For example, hemoglobin concentration was significantly decreased in the ≥125 mg/L male groups and 500 mg/L females. In males, despite the significant increase in erythrocyte count, these smaller erythrocytes (microcytosis) led to significant decreases in the hematocrit in the 250 mg/L and 500 mg/L groups. Additionally, MCH was significantly decreased in the ≥62.5 mg/L male and female mice.

Table 20 Summary of Select Hematology Data for Male and Female Mice in the Three-month Drinking Water Study of Sodium Metavanadate

Endpoint^a,b^ | 0 mg/L | 31.3 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L
Male
n | 10 | 10 | 9 | 10 | 10 | 9
Hematocrit (%) | 53.6 ± 0.4** | 54.1 ± 0.3 | 53.5 ± 0.4 | 52.4 ± 0.3 | 52.0 ± 0.6* | 51.4 ± 0.5**
Hemoglobin (g/dL) | 15.2 ± 0.1** | 15.5 ± 0.1 | 15.1 ± 0.1 | 14.7 ± 0.1** | 14.2 ± 0.2** | 13.7 ± 0.1**
Erythrocytes (10^6^/µL) | 10.50 ± 0.08** | 10.74 ± 0.05 | 10.71 ± 0.08 | 10.86 ± 0.11** | 11.60 ± 0.11** | 12.28 ± 0.11**
Reticulocytes (10^3^/µL) | 267.0 ± 7.0** | 262.7 ± 5.6 | 262.6 ± 6.7 | 273.1 ± 5.2 | 299.8 ± 9.7* | 368.2 ± 9.2**
Mean Cell Volume (fL) | 51.1 ± 0.2** | 50.4 ± 0.2* | 50.0 ± 0.2** | 48.3 ± 0.2** | 44.9 ± 0.2** | 41.9 ± 0.4**
Mean Cell Hemoglobin (pg) | 14.5 ± 0.1** | 14.4 ± 0.1 | 14.1 ± 0.1** | 13.5 ± 0.1** | 12.3 ± 0.1** | 11.1 ± 0.1**
Female
n | 10 | 9 | 9 | 9 | 9 | 10
Hematocrit (%) | 54.2 ± 0.7 | 55.0 ± 1.0 | 53.3 ± 0.7 | 53.9 ± 0.6 | 54.7 ± 1.2 | 53.6 ± 0.7
Hemoglobin (g/dL) | 15.7 ± 0.2** | 15.3 ± 0.6 | 15.4 ± 0.2 | 15.2 ± 0.1 | 14.9 ± 0.3 | 14.3 ± 0.2**
Erythrocytes (10^6^/µL) | 10.58 ± 0.17** | 10.81 ± 0.18 | 10.77 ± 0.14 | 11.57 ± 0.12** | 12.57 ± 0.19** | 13.25 ± 0.19**
Reticulocytes (10^3^/µL) | 310.8 ± 15.0** | 280.9 ± 19.1 | 268.5 ± 17.2 | 352.9 ± 16.1 | 406.8 ± 14.2** | 465.7 ± 13.6**
Mean Cell Volume (fL) | 51.3 ± 0.3** | 50.9 ± 0.3 | 49.5 ± 0.2** | 46.6 ± 0.1** | 43.5 ± 0.4** | 40.5 ± 0.3**
Mean Cell Hemoglobin (pg) | 14.8 ± 0.1** | 14.1 ± 0.4 | 14.3 ± 0.1** | 13.2 ± 0.1** | 11.9 ± 0.1** | 10.8 ± 0.2**

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

Male mice in the 500 mg/L group displayed significantly higher testicular spermatid counts and counts per gram of testis (39%–41%) (Table 21). Cauda epididymal weights were also significantly lower (12%), and sperm counts appeared lower (12%) but were not statistically significant. There were no correlating histopathological findings in the testis or epididymis that were clearly attributable to sodium metavanadate exposure. Female mice exposed to sodium metavanadate did not display any alterations in estrous cyclicity that were attributed to exposure (Appendix E).

Table 21 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Drinking Water Study of Sodium Metavanadate

Endpoint^a^ | 0 mg/L | 125 mg/L | 250 mg/L | 500 mg/L
n | 10 | 10 | 10 | 9
Weight (g)^b^
Cauda epididymis | 0.017 ± 0.001** | 0.018 ± 0.001 | 0.016 ± 0.001 | 0.015 ± 0.000*
Spermatid Measurements^c^
Spermatid heads (10^6^/g testis) | 103.8 ± 11.3** | 99.2 ± 7.1 | 123.0 ± 10.6 | 146.6 ± 8.7**
Spermatid heads (10^6^/testis) | 9.3 ± 0.9** | 9.5 ± 0.8 | 10.7 ± 1.2 | 12.9 ± 0.9*
Epididymal Spermatozoal Measurements
Sperm motility (%) | 85.2 ± 1.9 | 86.2 ± 1.8 | 84.1 ± 1.6 | 87.8 ± 1.6
Sperm (10^3^/mg cauda epididymis) | 1,981.7 ± 149.4 | 1,766.4 ± 80.7 | 2,034.2 ± 229.8 | 2,036.9 ± 85.3
Cauda epididymis sperm count (millions) | 34.5 ± 2.9 | 30.9 ± 1.5 | 31.8 ± 3.5 | 30.5 ± 1.3

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

##### Histopathology

This section describes the statistically significant or biologically noteworthy changes in the incidence of nonneoplastic lesions in the small intestine, large intestine, and kidney.

There were no gross lesions attributable to sodium metavanadate exposure in mice.

Small and large intestines: Epithelial hyperplasia was observed in the small and large intestines in male mice and in the small intestine in female mice (Table 22). These lesions were not observed in the control groups. Hyperplasia of the small intestinal epithelium in male mice was seen only in the ileum. It was observed in male mice exposed to ≥125 mg/L, with a positive trend and significant pairwise comparisons in the ≥250 mg/L groups, and the severity ranged from minimal to mild. In the large intestine, this lesion was seen in the colon of one high-exposure animal. This animal was euthanized moribund on study day 20 and exhibited erosion of the cecal epithelium. Epithelial hyperplasia was also seen in the colon of one male in the 500 mg/L group. Hyperplasia of the small intestinal epithelium in female mice was seen in the ileum and jejunum. In the ileum, epithelial hyperplasia was observed in female mice exposed to ≥125 mg/L, with a positive trend and significant pairwise comparisons in the ≥250 mg/L groups, and the severity ranged from minimal to mild. In the jejunum, epithelial hyperplasia was observed in one female in the 500 mg/L group. Incidences of epithelial hyperplasia in all intestinal sites (combined) were observed in males and females in the ≥125 mg/L groups, with a positive trend and significant pairwise comparisons in the ≥250 mg/L groups. This lesion was not observed in males and females exposed to ≤62.5 mg/L. Hyperplasia of the intestinal epithelium in mice was nearly identical to that described in rats exposed to sodium metavanadate (see Sodium Metavanadate Rat Histopathology).

Table 22 Incidences of Epithelial Hyperplasia of the Small and Large Intestines in Male and Female Mice in the Three-month Drinking Water Study of Sodium Metavanadate

| 0 mg/L | 31.3 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L
Male
n^a^ | 10 | 0 | 10 | 10 | 10 | 10
Intestine, Small, Ileum
Epithelium, hyperplasia^b^ | 0** | –^c^ | 0 | 2 (1.0)^d^ | 5* (2.0) | 7** (1.3)
Intestine, Large, Cecum
Erosion | 0 | – | – | – | – | 1 (2.0)
Intestine, Large, Colon
Epithelium, hyperplasia | 0 | – | – | – | 0 | 1 (1.0)
Intestine, Any Site | 10
Epithelium, hyperplasia | 0** | – | 0 | 2 | 5* | 7**
Female
n | 10 | 0 | 10 | 10 | 10 | 10
Intestine, Small, Ileum
Epithelium, hyperplasia | 0** | – | 0 | 2 (1.0) | 9** (1.7) | 8** (1.4)
Intestine, Small, Jejunum
Epithelium, hyperplasia | 0 | – | – | – | 0 | 1 (1.0)
Intestine, Any Site
Epithelium, hyperplasia | 0** | – | 0 | 2 | 9** | 8**

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion. Statistical analyses performed by Cochran-Armitage (trend) and Fisher’s exact (pairwise) one-sided tests.

^c^ Data were not collected for an exposed group when animals exposed to higher concentrations exhibited no incidences of nonneoplastic lesions in that tissue.

^d^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Kidney: In the kidneys of the male mice, renal tubule cytoplasmic alteration was seen in all animals in the 500 mg/L group and in two of the animals in the 250 mg/L group, and the severity increased with increasing exposure (Table 23). This lesion was not seen in the control group. This lesion was characterized by a decrease of the cytoplasmic vacuolation in relation to that of the control male mice.

Table 23 Incidences of Renal Tubule Cytoplasmic Alteration of the Kidney in Male Mice in the Three-month Drinking Water Study of Sodium Metavanadate

| 0 mg/L | 31.3 mg/L | 62.5 mg/L | 125 mg/L | 250 mg/L | 500 mg/L
Male
Kidney^a^ | 10 | 0 | 10 | 10 | 10 | 10
Renal tubule, cytoplasmic alteration^b^ | 0** | –^c^ | 0 | 0 | 2 (2.0)^d^ | 10** (2.7)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion. Statistical analyses performed by Cochran-Armitage (trend) and Fisher’s exact (pairwise) one-sided tests.

^c^ Data were not collected for an exposed group when animals exposed to higher concentrations exhibited no incidences of nonneoplastic lesions in that tissue.

^d^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

## Vanadyl Sulfate

### Rats

#### Three-month Study (Perinatal Phase)

During gestation or lactation, there was no effect on survival of dams due to vanadyl sulfate exposure (Table 24). There were no effects in vanadyl sulfate-exposed dams as indicated by pregnancy and littering rates being similar across all groups.

Table 24 Summary of the Disposition of F_0_ Female Rats during Perinatal Exposure in the Perinatal and Three-month Drinking Water Study of Vanadyl Sulfate

Reproductive Performance | 0 mg/L | 21.0 mg/L | 41.9 mg/L | 83.8 mg/L | 168 mg/L | 335 mg/L
Time-mated Females (GD 6) | 16 | 16 | 16 | 16 | 16 | 16
Females Pregnant (%)^a^ | 15 (93.8) | 16 (100) | 16 (100) | 16 (100) | 15 (93.8) | 16 (100)
Females Not Pregnant (%) | 1 (6.2) | 0 (0) | 0 (0) | 0 (0) | 1 (6.2) | 0 (0)
Pregnant Females Removed Prior to Littering (%)^b^ | 0 (0) | 0 (0) | 0 (0) | 0 (0) | 0 (0) | 1 (6.2)
Dams with Litters on LD 0 (%)^b^ | 15 (100) | 16 (100) | 16 (100) | 16 (100) | 15 (100) | 15 (100)
Gestation Length (Days)^c,d^ | 21.9 ± 0.1 (15) | 21.9 ± 0.1 (16) | 22.1 ± 0.1 (16) | 22.2 ± 0.1 (16) | 21.8 ± 0.1 (15) | 21.9 ± 0.1 (15)
Litters Poststandardization (PND 4)^e^ | 15 | 16 | 16 | 16 | 15 | 15
Litters at Weaning (LD 28) | 15 | 16 | 15 | 14 | 15 | 15
F_1_ Males/Females (PND 28)^f^ | 57/58 | 63/64 | 60/60 | 55/56 | 58/59 | 60/58

GD = gestation day; LD = lactation day; PND = postnatal day.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^b^ Percentage is given as a portion of pregnant dams.

^c^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^d^ Gestation length calculated for sperm-positive females that delivered a litter. Data are presented as mean ± standard error (number of dams).

^e^ Standardization to eight pups/litter (four pups/sex).

^f^ Number of males/females surviving until weaning on PND 28.

Gestational body weights of all exposed groups were within 10% of the control group, with a small but significant decrease in the 335 mg/L group (5%–6%) beginning on GD 18 (Table 25). Dam body weights during lactation were similar across all groups. There was a small but significant decrease on LD 1 in the 335 mg/L group (6%) that resolved by LD 4.

Table 25 Summary of Body Weights and Body Weight Gains of F_0_ Female Rats during Gestation and Lactation in the Perinatal and Three-month Drinking Water Study of Vanadyl Sulfate

Parameter^a,b^ | 0 mg/L | 21.0 mg/L | 41.9 mg/L | 83.8 mg/L | 168 mg/L | 335 mg/L
Gestation Body Weight
Gestation Day
6 | 245.5 ± 3.2 (15) | 244.8 ± 3.0 (16) | 244.7 ± 2.5 (16) | 242.7 ± 3.1 (16) | 243.3 ± 2.3 (15) | 242.8± 3.1 (16)
9 | 258.7 ± 3.5 (15) | 259.2 ± 3.2 (16) | 259.1 ± 3.1 (16) | 257.5 ± 3.2 (16) | 257.3 ± 2.4 (15) | 253.6 ± 3.9 (16)
12 | 273.7 ± 3.9* (15) | 273.2 ± 3.3 (16) | 273.2 ± 3.6 (16) | 270.9 ± 3.3 (16) | 269.7 ± 2.8 (15) | 264.7 ± 3.6 (16)
15 | 293.0 ± 3.7* (15) | 294.4 ± 3.8 (16) | 293.1 ± 4.2 (16) | 289.2 ± 3.7 (16) | 288.6 ± 2.9 (15) | 283.4 ± 4.2 (16)
18 | 334.3 ± 4.2** (15) | 337.1 ± 4.9 (16) | 334.4 ± 5.8 (16) | 327.6 ± 4.9 (16) | 325.2 ± 4.4 (15) | 318.8 ± 5.2* (16)
21 | 386.1 ± 4.6** (15) | 388.4 ± 5.7 (16) | 387.5 ± 8.2 (16) | 371.9 ± 5.8 (16) | 372.9 ± 6.7 (15) | 361.8 ± 7.6* (16)
Gestation Weight Change
Gestation Day Interval
6–9 | 13.1 ± 0.8 (15) | 14.4 ± 0.6 (16) | 14.4 ± 1.0 (16) | 14.8 ± 0.7 (16) | 14.1 ± 0.8 (15) | 10.9 ± 1.5 (16)
9–12 | 15.0 ± 0.8** (15) | 14.0 ± 0.9 (16) | 14.1 ± 0.9 (16) | 13.4 ± 0.7 (16) | 12.3 ± 1.3 (15) | 11.1 ± 0.7** (16)
12–15 | 19.3 ± 0.7 (15) | 21.2 ± 1.0 (16) | 19.9 ± 1.7 (16) | 18.3 ± 1.1 (16) | 18.9 ± 0.9 (15) | 18.6 ± 0.8 (16)
15–18 | 41.3 ± 1.5** (15) | 42.7 ± 1.6 (16) | 41.3 ± 2.2 (16) | 38.4 ± 2.3 (16) | 36.6 ± 2.0 (15) | 35.4 ± 1.7* (16)
18–21 | 51.8 ± 1.3* (15) | 51.3 ± 1.5 (16) | 53.1 ± 2.9 (16) | 44.4 ± 2.4 (16) | 47.7 ± 2.8 (15) | 43.0 ± 3.8 (16)
6–21 | 140.6 ± 2.3** (15) | 143.5 ± 4.0 (16) | 142.7 ± 6.8 (16) | 129.2 ± 4.3 (16) | 129.6 ± 5.9 (15) | 119.0 ± 5.7** (16)
Lactation Body Weight
Lactation Day
1 | 283.2 ± 4.4** (15) | 285.5 ± 4.3 (16) | 281.1 ± 3.8 (16) | 273.0 ± 5.0 (16) | 273.9 ± 3.0 (15) | 267.2 ± 4.9* (15)
4 | 290.4 ± 4.6* (15) | 290.5 ± 3.8 (16) | 291.0 ± 4.5 (16) | 283.3 ± 4.2 (16) | 284.3 ± 3.6 (15) | 277.3 ± 5.1 (15)
7 | 299.7 ± 4.3* (15) | 300.4 ± 3.3 (16) | 298.7 ± 4.7 (15) | 294.7 ± 4.5 (15) | 294.4 ± 4.0 (15) | 287.6 ± 5.2 (15)
10 | 306.2 ± 4.1 (15) | 306.1 ± 3.3 (16) | 306.3 ± 4.9 (15) | 307.3 ± 4.4 (15) | 303.4 ± 3.9 (15) | 299.8 ± 4.5 (15)
13 | 313.0 ± 4.1 (15) | 306.5 ± 3.4 (16) | 310.2 ± 4.6 (15) | 310.8 ± 4.9 (15) | 304.2 ± 4.6 (15) | 303.8 ± 4.7 (15)
16 | 316.8 ± 4.4 (15) | 314.3 ± 3.6 (16) | 320.8 ± 4.4 (15) | 313.1 ± 4.6 (15) | 314.6 ± 5.2 (15) | 304.5 ± 5.3 (15)
19 | 306.0 ± 4.3 (15) | 307.3 ± 4.0 (16) | 306.9 ± 3.8 (15) | 308.5 ± 4.3 (15) | 307.3 ± 4.0 (15) | 301.0 ± 4.3 (15)
21 | 300.5 ± 4.4 (15) | 304.6 ± 4.6 (16) | 306.3 ± 4.8 (15) | 302.6 ± 5.0 (14) | 301.5 ± 4.1 (15) | 296.1 ± 5.9 (15)
25 | 282.9 ± 5.7 (15) | 279.7 ± 3.8 (16) | 282.3 ± 4.4 (15) | 288.1 ± 4.4 (14) | 286.3 ± 4.1 (15) | 281.1 ± 4.6 (15)
28 | 285.3 ± 4.9 (15) | 278.0 ± 4.0 (16) | 282.3 ± 4.2 (15) | 285.0 ± 4.3 (14) | 285.7 ± 3.7 (15) | 280.8 ± 4.9 (15)
Lactation Weight Change
Lactation Day Interval
1–4 | 7.2 ± 1.6 (15) | 5.0 ± 3.5 (16) | 9.9 ± 2.0 (16) | 10.3 ± 2.0 (16) | 10.3 ± 1.9 (15) | 10.1 ± 1.8 (15)
4–7 | 9.2 ± 1.5 (15) | 9.9 ± 1.4 (16) | 7.5 ± 1.7 (15) | 9.9 ± 2.4 (15) | 10.1 ± 2.2 (15) | 10.3 ± 2.2 (15)
7–10 | 6.5 ± 2.3* (15) | 5.7 ± 2.5 (16) | 7.6 ± 2.2 (15) | 12.6 ± 2.8 (15) | 9.0 ± 2.3 (15) | 12.2 ± 2.3 (15)
10–13 | 6.8 ± 2.2 (15) | 0.4 ± 2.8 (16) | 3.9 ± 2.2 (15) | 3.5 ± 2.1 (15) | 0.7 ± 2.4 (15) | 4.1 ± 3.1 (15)
13–16 | 3.8 ± 1.7 (15) | 7.8 ± 2.3 (16) | 10.6 ± 2.1 (15) | 2.3 ± 2.4 (15) | 10.4 ± 2.7 (15) | 0.7 ± 3.6 (15)
16–19 | −10.8 ± 1.9 (15) | −7.0 ± 1.5 (16) | −13.9 ± 2.2 (15) | −4.5 ± 2.6 (15) | −7.3 ± 2.7 (15) | −3.5 ± 3.4 (15)
19–21 | −5.5 ± 2.0 (15) | −2.7 ± 2.2 (16) | −0.6 ± 3.1 (15) | −4.5 ± 2.1 (14) | −5.8 ± 2.3 (15) | −4.9 ± 3.0 (15)
21–25 | −17.6 ± 2.9 (15) | −24.8 ± 2.2 (16) | −24.0 ± 2.8 (15) | −14.5 ± 2.8 (14) | −15.2 ± 2.8 (15) | −15.0 ± 3.3 (15)
25–28 | 2.4 ± 1.9 (15) | −1.8 ± 1.1 (16) | 0.0 ± 2.8 (15) | −3.1 ± 2.2 (14) | −0.6 ± 2.1 (15) | −0.3 ± 2.4 (15)
1–28 | 2.1 ± 2.7** (15) | −7.5 ± 3.9 (16) | 0.5 ± 2.3 (15) | 8.4 ± 3.1 (14) | 11.8 ± 3.1* (15) | 13.6 ± 2.3** (15)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Each exposed group was compared to the vehicle control group with the Williams test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunnett test when no trend was present.

^b^ Data are presented as mean ± standard error (number of dams). Body weight data are presented in grams.

Water consumption during gestation (GD 6–21) was significantly decreased at ≥83.8 mg/L in a concentration-dependent manner, with rats in the 335 mg/L group consuming 37% less water than the control group (Table 26). Water consumption during lactation (LD 1–13) significantly decreased by 11% in the 335 mg/L group compared to the control group; all other exposed groups were similar to the control group during lactation. Vanadyl sulfate intake during gestation (GD 6–21) and lactation (LD 1–13) are presented in Table 26

Table 26 Summary of Water and Vanadyl Sulfate Consumption by F_0_ Female Rats during Gestation and Lactation in the Perinatal and Three-month Drinking Water Study

Parameter^a^ | 0 mg/L | 21.0 mg/L | 41.9 mg/L | 83.8 mg/L | 168 mg/L | 335 mg/L
Gestation Day Interval (g/kg/day)^b^
6–9 | 143.3 ± 7.0** (15) | 129.6 ± 4.0 (16) | 131.8 ± 3.2 (16) | 125.6 ± 4.5 (16) | 105.4 ± 3.1** (14) | 87.5 ± 3.6** (16)
9–12 | 145.8 ± 6.6** (15) | 134.6 ± 4.1 (16) | 135.0 ± 4.5 (16) | 129.2 ± 5.6* (16) | 106.2 ± 3.1** (15) | 90.2 ± 2.9** (16)
12–15 | 144.4 ± 8.2** (15) | 126.0 ± 3.3 (16) | 130.2 ± 4.1 (16) | 118.2 ± 4.0** (16) | 98.9 ± 3.5** (15) | 82.2 ± 3.0** (16)
15–18 | 168.9 ± 7.2** (15) | 153.5 ± 4.6 (16) | 163.0 ± 7.0 (16) | 143.2 ± 6.0** (16) | 129.1 ± 4.2** (15) | 112.6 ± 2.9** (16)
18–21 | 143.1 ± 5.8** (15) | 128.4 ± 3.9 (16) | 135.3 ± 6.4 (16) | 120.1 ± 4.4** (16) | 108.1 ± 4.2** (15) | 96.6 ± 2.6** (16)
6–21 | 147.6 ± 6.4** (15) | 133.0 ± 3.1 (16) | 137.9 ± 4.8 (16) | 126.0 ± 4.5** (16) | 108.9 ± 3.1** (15) | 93.5 ± 2.6** (16)
Lactation Day Interval (g/kg/day)^b^
1–4 | 182.7 ± 7.0** (15) | 174.0 ± 4.7 (16) | 170.5 ± 6.0 (16) | 163.1 ± 5.6* (16) | 165.5 ± 5.1* (15) | 157.0 ± 5.2** (15)
4–7 | 184.6 ± 6.6 (15) | 187.0 ± 3.9 (16) | 193.8 ± 5.7 (15) | 193.5 ± 4.1 (15) | 177.5 ± 5.3 (15) | 171.6 ± 3.8 (15)
7–10 | 220.3 ± 8.6 (15) | 215.2 ± 4.2 (16) | 226.1 ± 6.4 (15) | 231.7 ± 6.5 (15) | 210.8 ± 5.8 (15) | 200.2 ± 4.7 (15)
10–13 | 252.1 ± 9.3** (15) | 251.8 ± 5.6 (16) | 249.8 ± 7.3 (15) | 247.7 ± 6.6 (15) | 227.2 ± 8.3 (15) | 214.9 ± 4.9** (15)
1–13 | 210.6 ± 7.4** (15) | 208.0 ± 3.5 (16) | 211.8 ± 5.7 (15) | 211.1 ± 4.6 (15) | 196.5 ± 5.5 (15) | 187.3 ± 3.9** (15)
Chemical Intake (mg/kg/day)^c,d^
GD 6–21 | 0.0 ± 0.0 (15) | 2.8 ± 0.1 (16) | 5.8 ± 0.2 (16) | 10.6 ± 0.4 (16) | 18.3 ± 0.5 (15) | 31.3 ± 0.9 (16)
LD 1–13 | 0.0 ± 0.0 (15) | 4.4 ± 0.1 (16) | 8.9 ± 0.2 (15) | 17.7 ± 0.4 (15) | 33.0 ± 0.9 (15) | 62.8 ± 1.3 (15)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

GD = gestation day; LD = lactation day.

^a^ Data are presented as mean ± standard error (number of dams).

^b^ Each exposed group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^c^ Chemical intake calculated as: ([exposure concentration × water consumption]/[average body weight of day range]).

^d^ No statistical analysis was performed on the chemical intake data.

Vanadyl sulfate exposure did not significantly affect litter size or pup viability (Table 27). However, total and live litter sizes in the 335 mg/L group were 10% smaller than the control group at PND 0. There was a significant difference in live litter size on PND 0 in the 83.8 mg/L group, but this was considered a spurious finding attributable to a small increase in the number of dead pups on PND 0. Live litter size in the 168 mg/L group was similar to the control group, and therefore the lack of an exposure concentration-related response suggests the effects at 83.8 mg/L were not exposure concentration-related. Male and female pup body weights of vanadyl sulfate-exposed groups were within 5% of control groups throughout lactation (Table 28).

Table 27 Summary of Litter Size and Survival Ratio of F_1_ Male and Female Rats during Lactation in the Perinatal and Three-month Drinking Water Study of Vanadyl Sulfate

Postnatal Day | 0 mg/L | 21.0 mg/L | 41.9 mg/L | 83.8 mg/L | 168 mg/L | 335 mg/L
Total Litter Size^a,b^
0 | 14.5 ± 0.4 (15) | 14.4 ± 0.5 (16) | 13.9 ± 0.9 (16) | 13.0 ± 0.7 (16) | 13.7 ± 0.7 (15) | 13.0 ± 0.8 (15)
Live Litter Size^a,b^
0 | 14.2 ± 0.4 (15) | 13.9 ± 0.5 (16) | 13.1 ± 0.8 (16) | 11.8 ± 0.8* (16) | 13.3 ± 0.8 (15) | 12.8 ± 0.7 (15)
1 | 14.2 ± 0.4 (15) | 13.8 ± 0.5 (16) | 12.9 ± 0.8 (16) | 11.5 ± 0.9* (16) | 13.1 ± 0.8 (15) | 12.8 ± 0.7 (15)
4 (Prestandardization) | 14.1 ± 0.4 (15) | 13.8 ± 0.5 (16) | 12.8 ± 0.7 (16) | 11.4 ± 0.8* (16) | 13.1 ± 0.8 (15) | 12.7 ± 0.7 (15)
4 (Poststandardization) | 8.0 ± 0.0 (15) | 8.0 ± 0.0 (16) | 7.8 ± 0.3 (16) | 7.6 ± 0.3 (16) | 7.8 ± 0.2 (15) | 7.9 ± 0.1 (15)
7 | 7.9 ± 0.1 (15) | 7.9 ± 0.1 (16) | 8.0 ± 0.0 (15)^c^ | 7.9 ± 0.1 (15)^c^ | 7.8 ± 0.2 (15) | 7.9 ± 0.1 (15)
10 | 7.8 ± 0.1 (15) | 7.9 ± 0.1 (16) | 8.0 ± 0.0 (15) | 7.9 ± 0.1 (15) | 7.8 ± 0.2 (15) | 7.9 ± 0.1 (15)
13 | 7.7 ± 0.2 (15) | 7.9 ± 0.1 (16) | 8.0 ± 0.0 (15) | 7.9 ± 0.1 (15) | 7.8 ± 0.2 (15) | 7.9 ± 0.1 (15)
16 | 7.7 ± 0.2 (15) | 7.9 ± 0.1 (16) | 8.0 ± 0.0 (15) | 7.9 ± 0.1 (15) | 7.8 ± 0.2 (15) | 7.9 ± 0.1 (15)
19 | 7.7 ± 0.2 (15) | 7.9 ± 0.1 (16) | 8.0 ± 0.0 (15) | 7.9 ± 0.1 (15) | 7.8 ± 0.2 (15) | 7.9 ± 0.1 (15)
21 | 7.7 ± 0.2 (15) | 7.9 ± 0.1 (16) | 8.0 ± 0.0 (15) | 7.9 ± 0.1 (14)^c^ | 7.8 ± 0.2 (15) | 7.9 ± 0.1 (15)
25 | 7.7 ± 0.2 (15) | 7.9 ± 0.1 (16) | 8.0 ± 0.0 (15) | 7.9 ± 0.1 (14) | 7.8 ± 0.2 (15) | 7.9 ± 0.1 (15)
28 | 7.7 ± 0.2 (15) | 7.9 ± 0.1 (16) | 8.0 ± 0.0 (15) | 7.9 ± 0.1 (14) | 7.8 ± 0.2 (15) | 7.9 ± 0.1 (15)
% Live Male per Litter^a,b,d^
0 | 45.83 ± 3.23 (15) | 50.20 ± 3.21 (16) | 49.74 ± 4.86 (16) | 45.06 ± 4.44 (16) | 51.22 ± 4.41 (15) | 50.19 ± 4.09 (15)
No. of Dead Pups (Litters)^e,f^
0 | 4 (4) | 8 (5) | 13 (6) | 20 (7) | 7 (4) | 3 (2)
1–4 | 1 (1) | 1 (1) | 5 (4) | 5 (4) | 2 (1) | 1 (1)
5–28 | 5 (4) | 1 (1) | 0 (0) | 0 (0) | 0 (0) | 0 (0)
Dead per Litter^a,b,g^
0 | 0.27 ± 0.12 (15) | 0.50 ± 0.20 (16) | 0.81 ± 0.34 (16) | 1.25 ± 0.68 (16) | 0.47 ± 0.27 (15) | 0.20 ± 0.14 (15)
1–4 | 0.07 ± 0.07 (15) | 0.06 ± 0.06 (16) | 0.31 ± 0.15 (16) | 0.31 ± 0.15 (16) | 0.13 ± 0.13 (15) | 0.07 ± 0.07 (15)
5–28 | 0.33 ± 0.16** (15) | 0.06 ± 0.06 (16) | 0.00 ± 0.00* (15) | 0.00 ± 0.00* (14) | 0.00 ± 0.00** (15) | 0.00 ± 0.00** (15)
Survival Ratio^a,b^
0^h^ | 0.98 ± 0.01 (15) | 0.97 ± 0.01 (16) | 0.95 ± 0.02 (16) | 0.92 ± 0.04 (16) | 0.97 ± 0.02 (15) | 0.99 ± 0.01 (15)
1–4^i^ | 1.00 ± 0.00 (15) | 0.99 ± 0.01 (16) | 0.98 ± 0.01 (16) | 0.96 ± 0.03 (16) | 0.99 ± 0.01 (15) | 1.00 ± 0.00 (15)
5–28^j^ | 0.96 ± 0.02** (15) | 0.99 ± 0.01 (16) | 1.00 ± 0.00* (15) | 1.00 ± 0.00* (14) | 1.00 ± 0.00** (15) | 1.00 ± 0.00** (15)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean of the litter means ± standard error (number of litters).

^b^ Each exposed group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^c^ There were three dam and respective litter removals between LD 4 (poststandardization) and LD 20: two dams and respective litters were removed during litter standardizations on LD 4 due to insufficient litter sizes from the 41.9 mg/L and 83.8 mg/L groups, and one dam was found dead on LD 20 in the 83.3 mg/L group.

^d^ 100 × [number of live males in exposure group]/[number of live males and females in exposure group](number of pups).

^e^ Total number of dead pups in exposure group (number of litters contributing dead pups).

^f^ No statistical analysis was performed on this endpoint.

^g^ Number dead per litter (number of litters).

^h^ Survival per litter: Number of live pups on PND 0/total number of pups upon completion of parturition.

^i^ Survival per litter: Number of pups prestandardization on PND 4/total live pups on PND 0.

^j^ Survival per litter: Number of live pups on PND 28/number of live pups poststandardization on PND 4.

Table 28 Summary of Preweaning F_1_ Male and Female Rat Pup Body Weights Following Perinatal Exposure to Vanadyl Sulfate

Postnatal Day | 0 mg/L | 21.0 mg/L | 41.9 mg/L | 83.8 mg/L | 168 mg/L | 335 mg/L
Male
1^a,b,c^ | 7.09 ± 0.21 (98/15) | 7.07 ± 0.09 (110/16) | 7.31 ± 0.10 (107/15) | 7.00 ± 0.17 (86/15) | 7.05 ± 0.16 (100/15) | 7.06 ± 0.13 (96/15)
4^d,e,f,g^ | 9.93 ± 0.26 (97/15) | 10.36 ± 0.15 (110/16) | 10.44 ± 0.17 (107/15) | 9.99 ± 0.22 (86/15) | 10.15 ± 0.24 (100/15) | 10.21 ± 0.19 (96/15)
7^d,e,h^ | 15.76 ± 0.50 (58/15) | 16.96 ± 0.31 (63/16) | 17.11 ± 0.44 (60/15) | 17.09 ± 0.50 (59/15) | 16.11 ± 0.42 (58/15) | 16.46 ± 0.34 (60/15)
10^d,e,h^ | 23.33 ± 0.56 (58/15) | 24.38 ± 0.38 (63/16) | 24.67 ± 0.55 (60/15) | 24.32 ± 0.65 (59/15) | 23.70 ± 0.49 (58/15) | 23.78 ± 0.48 (60/15)
13^d,e,h^ | 31.49 ± 0.53 (58/15) | 32.15 ± 0.41 (63/16) | 32.55 ± 0.56 (60/15) | 32.24 ± 0.80 (59/15) | 31.66 ± 0.59 (58/15) | 31.27 ± 0.51 (60/15)
16^d,e,h^ | 38.88 ± 0.59 (58/15) | 39.11 ± 0.53 (63/16) | 39.24 ± 0.66 (60/15) | 39.05 ± 0.99 (59/15) | 38.27 ± 0.57 (58/15) | 37.69 ± 0.59 (60/15)
19^d,e,h^ | 48.53 ± 0.90* (57/15) | 49.61 ± 0.82 (63/16) | 50.17 ± 1.02 (60/15) | 49.17 ± 1.40 (59/15) | 47.83 ± 0.92 (58/15) | 46.90 ± 0.81 (60/15)
21^d,e,h^ | 57.44 ± 0.99** (57/15) | 59.04 ± 0.83 (63/16) | 59.53 ± 1.17 (60/15) | 58.61 ± 1.18 (55/14) | 56.37 ± 0.93 (58/15) | 55.61 ± 0.93 (60/15)
25^d,e,h^ | 74.64 ± 1.21* (57/15) | 77.25 ± 1.26 (63/16) | 77.47 ± 1.32 (60/15) | 76.98 ± 1.35 (55/14) | 73.88 ± 1.18 (58/15) | 73.75 ± 1.10 (60/15)
28^d,e,h^ | 92.26 ± 1.53** (57/15) | 94.53 ± 1.32 (63/16) | 95.50 ± 1.56 (60/15) | 94.40 ± 1.38 (55/14) | 89.32 ± 1.46 (58/15) | 88.73 ± 1.21 (60/15)
Female
1 | 6.52 ± 0.11 (115/15) | 6.75 ± 0.11 (111/16) | 6.87 ± 0.17 (100/16) | 6.76 ± 0.21 (98/16) | 6.70 ± 0.14 (97/15) | 6.81 ± 0.16 (96/15)
4 | 9.24 ± 0.23 (115/15) | 9.91 ± 0.19 (111/16) | 9.95 ± 0.16 (97/16) | 9.92 ± 0.29 (97/16) | 9.57 ± 0.23 (97/15) | 9.79 ± 0.21 (95/15)
7 | 14.42 ± 0.43 (60/15) | 16.08 ± 0.35* (64/16) | 16.30 ± 0.5** (60/15) | 17.19 ± 0.37** (60/15) | 15.19 ± 0.43 (59/15) | 15.61 ± 0.40 (58/15)
10 | 21.44 ± 0.60 (59/15) | 23.29 ± 0.49 (64/16) | 23.59 ± 0.64* (60/15) | 24.26 ± 0.47** (60/15) | 22.52 ± 0.51 (59/15) | 22.56 ± 0.56 (58/15)
13 | 29.35 ± 0.64 (58/15) | 30.99 ± 0.61 (64/16) | 31.25 ± 0.62 (60/15) | 32.08 ± 0.68* (60/15) | 30.40 ± 0.61 (59/15) | 29.84 ± 0.58 (58/15)
16 | 36.49 ± 0.68 (58/15) | 37.57 ± 0.73 (64/16) | 37.78 ± 0.71 (60/15) | 38.68 ± 0.88 (60/15) | 36.91 ± 0.60 (59/15) | 35.94 ± 0.63 (58/15)
19 | 45.47 ± 0.87* (58/15) | 47.65 ± 1.03 (64/16) | 47.49 ± 0.94 (60/15) | 48.37 ± 1.06 (60/15) | 45.73 ± 0.91 (59/15) | 44.67 ± 0.92 (58/15)
21 | 53.34 ± 0.98* (58/15) | 55.80 ± 1.06 (64/16) | 56.05 ± 1.03 (60/15) | 56.93 ± 0.73 (56/14) | 53.47 ± 0.99 (59/15) | 52.27 ± 0.99 (58/15)
25 | 68.06 ± 1.14 (58/15) | 71.31 ± 1.36 (64/16) | 71.73 ± 1.22 (60/15) | 72.95 ± 0.93* (56/14) | 68.64 ± 1.13 (59/15) | 68.13 ± 1.11 (58/15)
28 | 82.88 ± 1.52** (58/15) | 85.24 ± 1.45 (64/16) | 86.19 ±1.46 (60/15) | 86.87 ± 0.76 (56/14) | 81.91 ± 1.17 (59/15) | 80.18 ± 1.07 (58/15)
Male and Female
1 | 6.77 ± 0.15 (213/15) | 6.91 ± 0.08 (221/16) | 7.06 ± 0.13 (207/16) | 6.85 ± 0.21 (184/16) | 6.90 ± 0.15 (197/15) | 6.96 ± 0.14 (192/15)
4 | 9.57 ± 0.23 (212/15) | 10.15 ± 0.15 (221/16) | 10.15 ± 0.17 (204/16) | 9.88 ± 0.29 (183/16) | 9.90 ± 0.23 (197/15) | 10.00 ± 0.19 (191/15)
7 | 15.08 ± 0.46 (118/15) | 16.52 ± 0.30* (127/16) | 16.70 ± 0.45* (120/15) | 17.19 ± 0.40** (119/15) | 15.64 ± 0.42 (117/15) | 16.05 ± 0.34 (118/15)
10 | 22.38 ± 0.57 (117/15) | 23.83 ± 0.39 (127/16) | 24.13 ± 0.57 (120/15) | 24.35 ± 0.51* (119/15) | 23.11 ± 0.49 (117/15) | 23.19 ± 0.49 (118/15)
13 | 30.43 ± 0.57 (116/15) | 31.57 ± 0.46 (127/16) | 31.91 ± 0.55 (120/15) | 32.22 ± 0.71 (119/15) | 31.01 ± 0.59 (117/15) | 30.59 ± 0.50 (118/15)
16 | 37.67 ± 0.61 (116/15) | 38.33 ± 0.57 (127/16) | 38.51 ± 0.64 (120/15) | 38.93 ± 0.91 (119/15) | 37.59 ± 0.56 (117/15) | 36.84 ± 0.57 (118/15)
19 | 46.97 ± 0.86* (115/15) | 48.62 ± 0.85 (127/16) | 48.84 ± 0.93 (120/15) | 48.85 ± 1.18 (119/15) | 46.78 ± 0.90 (117/15) | 45.82 ± 0.78 (118/15)
21 | 55.36 ± 0.96** (115/15) | 57.41 ± 0.86 (127/16) | 57.79 ± 1.02 (120/15) | 57.89 ± 0.88 (111/14) | 54.89 ± 0.94 (117/15) | 53.99 ± 0.89 (118/15)
25 | 71.32 ± 1.13* (115/15) | 74.28 ± 1.21 (127/16) | 74.60 ± 1.15 (120/15) | 75.10 ± 1.03 (111/14) | 71.22 ± 1.13 (117/15) | 71.02 ± 1.01 (118/15)
28 | 87.55 ± 1.49** (115/15) | 89.88 ± 1.25 (127/16) | 90.85 ± 1.43 (120/15) | 90.80 ± 0.92 (111/14) | 85.52 ± 1.30 (117/50) | 84.57 ± 1.04 (118/15)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error (number of pups/number of litters). Body weight data are presented in grams.

^b^ Each exposed group was compared to the vehicle control group with the Williams test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunnett test when no trend was present.

^c^ Total pup weight on postnatal day (PND) 1 divided by number of live pups on PND 1.

^d^ Data are presented as mean of the litter means ± standard error (number of pups/number of litters). Body weight data are presented in grams.

^e^ Statistical analysis performed using mixed models with random litter effect for both trend and pairwise tests, using the Dunnett-Hsu adjustment for multiple comparisons.

^f^ PND 4 prestandardization.

^g^ Individual pup weights first adjusted for live litter size on PND 1.

^h^ Individual pup weights first adjusted for live litter size on PND 4 poststandardization.

#### Three-month Study (Postweaning Phase)

All male and female rats survived until the end of the study, and terminal body weights of the exposed groups were approximately equal to the control groups (Table 29, Table 30; Figure 4).

Table 29 Summary of Survival and Body Weights of Male Rats in the Perinatal and Three-month Drinking Water Study of Vanadyl Sulfate

Postnatal Day | 0 mg/L | | 21.0 mg/L | | | 41.9 mg/L | | | 83.8 mg/L | | | 168 mg/L | | | 335 mg/L
Postnatal Day | Wt. (g)^a,b^ | n^c^ | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n
28^d^ | 91.8 ± 2.0 | 15 (12) | 94.1 ± 1.4 | 102.5 | 15 (14) | 92.4 ± 2.4 | 100.6 | 15 (11) | 93.5 ± 2.5 | 101.9 | 14 (11) | 89.6 ± 1.5 | 97.5 | 15 (12) | 89.9 ± 1.3 | 97.9 | 15 (13)
35 | 131.2 ± 3.3* | 15 (12) | 129.3 ± 2.0 | 98.6 | 15 (14) | 132.4 ± 3.0 | 100.9 | 15 (11) | 131.2 ± 4.8 | 100.0 | 14 (11) | 129.0 ± 1.8 | 98.3 | 15 (12) | 122.9 ± 2.0 | 93.7 | 15 (13)
42 | 177.1 ± 4.6* | 15 (12) | 174.8 ± 3.4 | 98.7 | 15 (14) | 179.6 ± 4.4 | 101.4 | 15 (11) | 176.9 ± 5.6 | 99.9 | 14 (11) | 174.7 ± 2.3 | 98.6 | 15 (12) | 165.7 ± 2.9 | 93.6 | 15 (13)
49 | 224.5 ± 5.4** | 15 (12) | 226.1 ± 4.0 | 100.7 | 15 (14) | 229.1 ± 4.6 | 102.0 | 15 (11) | 226.1 ± 6.9 | 100.7 | 14 (11) | 221.1 ± 2.5 | 98.5 | 15 (12) | 209.4 ± 3.8 | 93.3 | 15 (13)
56 | 267.7 ± 6.5** | 15 (12) | 271.9 ± 4.5 | 101.6 | 15 (14) | 275.6 ± 4.9 | 103.0 | 15 (11) | 271.8 ± 7.1 | 101.5 | 14 (11) | 264.6 ± 3.4 | 98.8 | 15 (12) | 252.5 ± 3.8 | 94.3 | 15 (13)
63 | 310.3 ± 6.8** | 15 (12) | 313.9 ± 5.1 | 101.2 | 15 (14) | 316.5 ± 5.5 | 102.0 | 15 (11) | 311.9 ± 7.8 | 100.5 | 14 (11) | 304.6 ± 4.0 | 98.2 | 15 (12) | 294.9 ± 3.8 | 95.0 | 15 (13)
70 | 342.3 ± 7.8** | 15 (12) | 346.7 ± 5.3 | 101.3 | 15 (14) | 346.7 ± 5.5 | 101.3 | 15 (11) | 343.8 ± 8.1 | 100.5 | 14 (11) | 330.7 ± 4.6 | 96.6 | 15 (12) | 321.8 ± 4.9 | 94.0 | 15 (13)
77 | 365.7 ± 8.9** | 15 (12) | 371.2 ± 5.9 | 101.5 | 15 (14) | 371.2 ± 5.9 | 101.5 | 15 (11) | 368.3 ± 8.6 | 100.7 | 14 (11) | 354.9 ± 5.9 | 97.0 | 15 (12) | 347.0 ± 5.1 | 94.9 | 15 (13)
84 | 386.9 ± 9.3** | 15 (12) | 392.5 ± 7.1 | 101.4 | 15 (14) | 390.2 ± 6.6 | 100.8 | 15 (11) | 386.1 ± 8.9 | 99.8 | 14 (11) | 373.0 ± 6.4 | 96.4 | 15 (12) | 364.2 ± 5.5 | 94.1 | 15 (13)
91 | 400.8 ± 10.5** | 15 (12) | 410.7 ± 7.7 | 102.5 | 15 (14) | 407.2 ± 7.0 | 101.6 | 15 (11) | 402.7 ± 9.4 | 100.5 | 14 (11) | 388.3 ± 6.4 | 96.9 | 15 (12) | 377.2 ± 6.1 | 94.1 | 15 (13)
98 | 416.3 ± 10.7* | 15 (12) | 419.2 ± 9.0 | 100.7 | 15 (14) | 422.3 ± 7.9 | 101.4 | 15 (11) | 418.9 ± 9.5 | 100.6 | 14 (11) | 403.7 ± 6.7 | 97.0 | 15 (12) | 397.3 ± 5.5 | 95.4 | 15 (13)
105 | 426.3 ± 11.7* | 15 (12) | 442.2 ± 9.1 | 103.7 | 15 (14) | 432.5 ± 8.0 | 101.5 | 15 (11) | 434.9 ± 10.5 | 102.0 | 13 (10) | 415.1 ± 7.4 | 97.4 | 15 (12) | 406.1 ± 5.4 | 95.3 | 15 (13)
112 | 438.6 ± 11.5** | 15 (12) | 454.4 ± 8.0 | 103.6 | 15 (14) | 442.9 ± 8.6 | 101.0 | 15 (11) | 440.4 ± 11.4 | 100.4 | 14 (11) | 415.2 ± 9.7 | 94.7 | 15 (12) | 415.9 ± 6.2 | 94.8 | 15 (13)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Statistical analysis performed using mixed models with random litter effect for both trend and pairwise tests, using the Dunnett-Hsu adjustment for multiple comparisons.

^b^ Weights shown are mean of the litter means ± standard error.

^c^ Number of individual animals (number of litters); includes F_1_ core and investigative study animals.

^d^ Postnatal day 28 is the day animals were placed on study after pups were weaned.

Table 30 Summary of Survival and Body Weights of Female Rats in the Perinatal and Three-month Drinking Water Study of Vanadyl Sulfate

Postnatal Day | 0 mg/L | | 21.0 mg/L | | | 41.9 mg/L | | | 83.8 mg/L | | | 168 mg/L | | | 335 mg/L
Postnatal Day | Wt. (g)^a,b^ | n^c^ | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n
28^d^ | 84.2 ± 2.1* | 15 (12) | 85.0 ± 1.5 | 101.0 | 15 (14) | 86.1 ± 2.8 | 102.3 | 15 (11) | 87.4 ± 1.3 | 103.9 | 14 (11) | 82.4 ± 1.8 | 98.0 | 15 (12) | 80.5 ± 1.4 | 95.7 | 15 (13)
35 | 113.3 ± 2.7** | 15 (12) | 114.3 ± 2.1 | 100.9 | 15 (14) | 117.6 ± 3.0 | 103.8 | 15 (11) | 114.7 ± 1.7 | 101.2 | 14 (11) | 111.5 ± 2.0 | 98.4 | 15 (12) | 104.3 ± 1.8* | 92.1 | 15 (13)
42 | 142.6 ± 3.6** | 15 (12) | 145.4 ± 2.7 | 101.9 | 15 (14) | 151.0 ± 3.7 | 105.9 | 15 (11) | 147.5 ± 3.1 | 103.4 | 14 (11) | 145.0 ± 2.2 | 101.7 | 15 (12) | 134.5 ± 2.3 | 94.3 | 15 (13)
49 | 172.8 ± 3.8** | 15 (12) | 171.4 ± 3.1 | 99.2 | 15 (14) | 176.2 ± 4.0 | 102.0 | 15 (11) | 173.1 ± 3.5 | 100.2 | 14 (11) | 172.2 ± 2.9 | 99.7 | 15 (12) | 162.0 ± 2.3 | 93.8 | 15 (13)
56 | 192.3 ± 4.2* | 15 (12) | 195.3 ± 3.8 | 101.6 | 15 (14) | 196.7 ± 4.5 | 102.3 | 15 (11) | 193.7 ± 4.0 | 100.7 | 14 (11) | 195.1 ± 3.7 | 101.4 | 15 (12) | 182.5 ± 1.8 | 94.9 | 15 (13)
63 | 212.8 ± 4.8 | 15 (12) | 210.3 ± 3.9 | 98.8 | 15 (14) | 216.0 ± 4.9 | 101.5 | 15 (11) | 214.0 ± 3.8 | 100.5 | 14 (11) | 214.6 ± 4.2 | 100.9 | 15 (12) | 204.2 ± 3.1 | 95.9 | 15 (13)
70 | 224.2 ± 4.8 | 15 (12) | 225.7 ± 4.8 | 100.7 | 15 (14) | 230.3 ± 5.1 | 102.7 | 15 (11) | 225.1 ± 5.1 | 100.4 | 14 (11) | 228.5 ± 4.6 | 101.9 | 15 (12) | 215.8 ± 2.2 | 96.3 | 15 (13)
77 | 239.6 ± 6.9 | 15 (12) | 237.3 ± 4.5 | 99.0 | 15 (14) | 243.8 ± 6.6 | 101.8 | 15 (11) | 238.2 ± 4.8 | 99.4 | 14 (11) | 241.0 ± 5.4 | 100.6 | 15 (12) | 230.8 ± 2.7 | 96.3 | 15 (13)
84 | 248.4 ± 5.7 | 15 (12) | 247.5 ± 5.2 | 99.6 | 15 (14) | 254.3 ± 6.2 | 102.4 | 15 (11) | 252.4 ± 4.8 | 101.6 | 14 (11) | 253.0 ± 7.2 | 101.8 | 15 (12) | 237.6 ± 3.7 | 95.6 | 15 (13)
91 | 251.4 ± 5.7 | 15 (12) | 258.4 ± 6.0 | 102.8 | 15 (14) | 262.1 ± 6.8 | 104.2 | 15 (11) | 255.4 ± 5.5 | 101.6 | 14 (11) | 259.0 ± 6.1 | 103.0 | 15 (12) | 249.3 ± 4.3 | 99.2 | 15 (13)
98 | 263.6 ± 6.3 | 15 (12) | 262.7 ± 4.8 | 99.7 | 15 (14) | 269.0 ± 6.5 | 102.0 | 15 (11) | 260.4 ± 6.0 | 98.8 | 14 (11) | 265.1 ± 5.1 | 100.6 | 15 (12) | 255.4 ± 4.0 | 96.9 | 15 (13)
105 | 267.4 ± 7.8 | 15 (12) | 265.1 ± 5.1 | 99.1 | 15 (14) | 272.9 ± 7.2 | 102.0 | 15 (11) | 266.6 ± 5.1 | 99.7 | 14 (11) | 272.0 ± 6.6 | 101.7 | 15 (12) | 261.1 ± 3.0 | 97.7 | 15 (13)
112 | 267.6 ± 6.4 | 15 (12) | 272.6 ± 4.7 | 101.9 | 15 (14) | 279.9 ± 7.5 | 104.6 | 15 (11) | 272.2 ± 5.6 | 101.7 | 14 (11) | 277.1 ± 6.6 | 103.6 | 15 (12) | 265.3 ± 3.7 | 99.2 | 15 (13)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Statistical analysis performed using mixed models with random litter effect for both trend and pairwise tests, using the Dunnett-Hsu adjustment for multiple comparisons.

^b^ Weights shown are mean of the litter means ± standard error.

^c^ Number of individual animals (number of litters); includes F_1_ core and investigative study animals.

^d^ Postnatal day 28 is the day animals were placed on study after pups were weaned.

Figure 4

Growth Curves for Male and Female Rats in the Perinatal and Three-month Drinking Water Study of Vanadyl Sulfate

Growth curves are shown for (A) males and (B) females.

Water consumption was reduced in a concentration-dependent manner during the postweaning phase (PND 28–112) (Table 31). In male rats, there were significant decreases in water consumption by the 83.8 (10%), 168 (13%), and 335 (21%) mg/L groups for the duration of PND 28–112. In female rats, there was a significant decrease in water consumption over the PND 28–112 interval in the 335 (24%) mg/L group. Vanadyl sulfate intake over the 3-month postweaning phase (PND 28–112) is presented in Table 31.

Table 31 Summary of Water and Vanadyl Sulfate Consumption by Male and Female Rats in the Perinatal and Three-month Drinking Water Study

Postnatal Day^a^ | 0 mg/L | 21.0 mg/L | 41.9 mg/L | 83.8 mg/L | 168 mg/L | 335 mg/L
Male (g/kg/day)^b^
28–35 | 168.1 ± 7.7 (9) | 151.5 ± 9.4 (9) | 163.2 ± 6.1 (10) | 160.6 ± 10.4 (9) | 162.3 ± 3.0 (11) | 143.4 ± 3.0* (9)
49–56 | 137.5 ± 4.2** (9) | 132.4 ± 5.1 (9) | 129.5 ± 3.9 (10) | 123.5 ± 3.7* (10) | 118.1 ± 2.8** (11) | 112.4 ± 2.7** (9)
70–77 | 86.0 ± 2.0** (9) | 83.0 ± 2.1 (9) | 80.6 ± 2.6 (10) | 78.2 ± 2.4* (10) | 72.6 ± 1.6** (11) | 67.6 ± 1.3** (9)
105–112 | 63.0 ± 2.7** (9) | 58.5 ± 1.9 (9) | 57.9 ± 1.8 (10) | 55.1 ± 2.0* (10) | 52.0 ± 1.3** (11) | 47.3 ± 0.5** (9)
28–112 | 95.2 ± 2.8** (9) | 90.3 ± 2.8 (9) | 89.0 ± 1.8 (10) | 85.8 ± 2.8* (10) | 82.7 ± 1.8** (11) | 75.3 ± 0.8** (9)
Chemical Intake (mg/kg/day)^c,d^
28–112 | 0.0 ± 0.0 (9) | 1.9 ± 0.1 (9) | 3.7 ± 0.1 (10) | 7.2 ± 0.2 (10) | 13.9 ± 0.3 (11) | 25.2 ± 0.3 (9)
Female (g/kg/day)
28–35 | 159.3 ± 10.4 (6) | 158.9 ± 11.3 (6) | 172.1 ± 7.7 (9) | 172.2 ± 8.9 (8) | 164.2 ± 6.9 (8) | 150.3 ± 7.4 (7)
49–56 | 138.6 ± 11.5 (6) | 122.1 ± 6.5 (6) | 124.4 ± 4.8 (9) | 125.7 ± 5.0 (8) | 128.5 ± 5.7 (8) | 115.8 ± 3.4 (7)
70–77 | 108.1 ± 10.1* (6) | 93.0 ± 4.8 (6) | 97.9 ± 3.1 (9) | 100.4 ± 5.2 (8) | 96.9 ± 3.2 (8) | 78.7 ± 2.4** (7)
105–112 | 90.6 ± 10.6* (6) | 72.8 ± 8.1 (6) | 81.2 ± 4.1 (9) | 87.6 ± 7.5 (8) | 75.4 ± 4.1 (8) | 61.2 ± 3.0* (7)
28–112 | 117.1 ± 10.9* (6) | 98.9 ± 5.1 (6) | 106.3 ± 3.1 (9) | 109.8 ± 5.2 (8) | 101.5 ± 3.6 (8) | 89.1 ± 2.8* (7)
Chemical Intake (mg/kg/day)
28–112 | 0.0 ± 0.0 (6) | 2.1 ± 0.1 (6) | 4.5 ± 0.1 (9) | 9.2 ± 0.4 (8) | 17.1 ± 0.6 (8) | 29.9 ± 1.0 (7)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error (number of cages).

^b^ Each exposed group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^c^ Chemical intake calculated as: ([exposure concentration × water consumption]/[average body weight of day range]).

^d^ No statistical analysis was performed on the chemical intake data.

Vanadyl sulfate exposure had no effect on time to attainment of BPS in male rats (Appendix E). There was a positive trend for the day of VO attainment when data were unadjusted or adjusted for body weight at weaning (Table 32). Although not statistically significant, VO was 1.8 days or 1.6 days later in the 335 mg/L group when unadjusted or adjusted for body weight at weaning, respectively, compared to the control group.

Table 32 Summary of Vaginal Opening of F_1_ Female Rats Exposed to Vanadyl Sulfate in the Perinatal and Three-month Drinking Water Study

Parameter^a^ | 0 mg/L | 21.0 mg/L | 41.9 mg/L | 83.8 mg/L | 168 mg/L | 335 mg/L
No. Examined^b^ | 15 (12) | 15 (14) | 15 (11) | 14 (11) | 15 (12) | 15 (13)
No. Not Attaining^c^ | 0 | 0 | 0 | 0 | 0 | 0
Day of VO
Litter mean^d,e^ | 37.7 ± 0.5** | 37.3 ± 0.7 | 36.6 ± 0.5 | 36.7 ± 1.0 | 37.7 ± 0.6 | 39.5 ± 0.6
Adjusted litter mean^d,f,g^ | 37.7 ± 0.5* | 37.3 ± 0.7 | 36.7 ± 0.5 | 36.8 ± 1.0 | 37.6 ± 0.6 | 39.3 ± 0.6
Body Weight at Attainment (g)^h^ | 125.2 ± 3.4 | 123.4 ± 3.6 | 124.3 ± 3.2 | 122.8 ± 4.6 | 124.7 ± 3.7 | 122.1 ± 1.8
Body Weight at Weaning (g)^h^ | 84.8 ± 2.2* | 84.8 ± 1.6 | 85.6 ± 2.9 | 87.2 ± 1.2 | 82.6 ± 1.7 | 80.6 ± 1.4

Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

VO = vaginal opening.

^a^ Data are displayed as mean ± standard error unless otherwise noted; values are based on litter means, not individual pup values.

^b^ No. Examined = the number of pups examined (number of litters).

^c^ No. Not Attaining = number of pups that survived to the end of the observation period without attaining VO.

^d^ Summary statistics and mixed model results are presented for animals that attained during the observation period.

^e^ Statistical analysis performed using mixed effects models with exposure concentration as a covariate, litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^f^ Statistical analysis performed using mixed effects models with exposure concentration and weaning weight as covariates, litter as a random effect for both trend and pairwise tests, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

^g^ Adjusted based on body weight at weaning.

^h^ Analysis of body weight at attainment and body weight at weaning for both linear trend and pairwise comparisons performed using mixed effects models with exposure concentration as a covariate, litter as a random effect, and a Dunnett-Hsu adjustment for multiple pairwise comparisons.

Several spurious significant organ weight changes were observed and were not considered related to vanadyl sulfate exposure (Appendix E).

Male rats in the 168 and 335 mg/L groups displayed a slight (8%) but significant increase in cauda epididymal weights (Appendix E). No vanadyl sulfate-related changes in sperm counts, sperm motility, or histopathology in male reproductive organs were observed. In females, there was no effect of vanadyl sulfate on the number of estrous cycles or cycle length. Time in proestrus was lower in the 168 and 335 mg/L groups compared to the control group. Markov model estimates of stage length indicated that the length of proestrus was significantly decreased in the 335 mg/L group (Appendix E).

There were no hematology changes at PND 28 in F_1_ rats following vanadyl sulfate exposure (Appendix E). There were no changes in hematology or clinical chemistry attributed to vanadyl sulfate exposure in rats at the end of the study (Appendix E).

##### Histopathology

This section describes the statistically significant or biologically noteworthy changes in the incidence of nonneoplastic lesions in the small and large intestines.

Small and large intestines: Epithelial hyperplasia was observed in the ileum of the small intestine and the cecum of the large intestine (Table 33). As with the sodium metavanadate studies, this lesion was most prevalent in the ileum of the small intestine. In males, this lesion was seen in the ileum in the ≥168 mg/L groups, with a positive trend and a significant pairwise comparison in the 335 mg/L group. The severity of this lesion increased slightly with increasing exposure concentration. Epithelial hyperplasia of the ileum was significantly increased in females in the ≥168 mg/L groups, with a positive trend. This lesion was also seen in the cecum in males and females in the 335 mg/L groups, with a positive trend and significant pairwise comparisons. Severity was comparable between males and females. Incidences of epithelial hyperplasia were observed at all intestinal sites (combined) in males and females exposed to ≥168 mg/L, with a positive trend and significant pairwise comparisons in the 335 mg/L male and ≥168 mg/L female groups. The lesion occurred in the ileum of all but one male and one female in the 335 mg/L groups. Epithelial hyperplasia was not observed in males or females exposed to ≤83.8 mg/L. The histological appearance of the epithelial hyperplasia was identical to that seen in rats exposed to sodium metavanadate (see Sodium Metavanadate Rat Histopathology). One male in the 335 mg/L group had a minimal amount of mineral in the wall of the jejunum. It is unclear whether this lesion was related to exposure.

Table 33 Incidences of Epithelial Hyperplasia of the Small and Large Intestines in Male and Female Rats in the Perinatal and Three-month Drinking Water Study of Vanadyl Sulfate

| 0 mg/L | 21.0 mg/L | 41.9 mg/L | 83.8 mg/L | 168 mg/L | 335 mg/L
Male
n^a^ | 10 | 0 | 0 | 0^b^ | 10 | 10
Intestine, Small, Ileum
Epithelium, hyperplasia^c^ | 0** | –^d^ | – | – | 3 (1.0)^e^ | 9** (1.2)
Intestine, Large, Cecum
Epithelium, hyperplasia | 0* | – | – | – | 0 | 4* (1.0)
Intestine, Any Site
Epithelium, hyperplasia | 0** | – | – | 0 | 3 | 9**
Female
n | 10 | 0 | 10 | 10 | 10 | 10
Intestine, Small, Ileum
Epithelium, hyperplasia | 0** | – | 0 | 0 | 4* (1.3) | 9** (1.4)
Intestine, Large, Cecum
Epithelium, hyperplasia | 0* | – | – | – | 0 | 4* (1.0)
Intestine, Any Site
Epithelium, hyperplasia | 0** | – | 0 | 0 | 4* | 10**

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ For the intestine, any site data, n = 3 for the male 83.8 mg/L group.

^c^ Number of animals with lesion. Statistical analyses performed by Cochran-Armitage (trend) and Fisher’s exact (pairwise) one-sided tests.

^d^ Data were not collected for an exposed group when animals exposed to higher concentrations exhibited no incidences of nonneoplastic lesions in that tissue.

^e^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

### Mice

#### Three-month Study

There was no effect on survival of male or female mice due to vanadyl sulfate exposure (Table 34, Table 35; Figure 5). Significant decreases in body weight were consistently observed throughout the study in males in the 335 mg/L group, and terminal body weights were significantly decreased in the 168 mg/L group by 10% and in the 335 mg/L group by 13%. Although not significant, terminal body weight of the 335 mg/L females was slightly lower (9%) than that of the control group.

Table 34 Summary of Survival and Body Weights of Male Mice in the Three-month Drinking Water Study of Vanadyl Sulfate

Study Day^a^ | 0 mg/L | | 21.0 mg/L | | | | 41.9 mg/L | | | 83.8 mg/L | | | 168 mg/L | | | 335 mg/L
Study Day^a^ | Wt. (g)^b,c^ | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n
0 | 21.3 ± 0.3 | 10 | 21.3 ± 0.3 | 99.7 | 10 | 21.4 ± 0.4 | | 100.1 | 10 | 21.4 ± 0.3 | 100.2 | 10 | 21.2 ± 0.4 | 99.5 | 10 | 21.4 ± 0.3 | 100.0 | 10
7 | 23.2 ± 0.3 | 10 | 23.1 ± 0.3 | 99.6 | 10 | 23.1 ± 0.4 | | 99.7 | 10 | 23.1 ± 0.4 | 99.7 | 10 | 22.9 ± 0.3 | 98.8 | 10 | 22.4 ± 0.3 | 96.5 | 10
14 | 24.4 ± 0.3 | 10 | 24.4 ± 0.3 | 100.1 | 10 | 24.6 ± 0.4 | | 100.9 | 10 | 24.3 ± 0.4 | 99.9 | 10 | 24.0 ± 0.4 | 98.6 | 10 | 23.3 ± 0.4 | 95.6 | 10
21 | 26.1 ± 0.4** | 10 | 25.8 ± 0.4 | 99.0 | 10 | 25.9 ± 0.4 | | 99.3 | 10 | 25.8 ± 0.5 | 99.0 | 10 | 25.3 ± 0.3 | 96.7 | 10 | 24.3 ± 0.4** | 93.1 | 10
28 | 27.4 ± 0.5** | 10 | 27.2 ± 0.4 | 99.1 | 10 | 27.0 ± 0.5 | | 98.6 | 10 | 27.4 ± 0.6 | 99.9 | 10 | 26.3 ± 0.3 | 96.0 | 10 | 25.4 ± 0.4** | 92.5 | 10
35 | 29.0 ± 0.6** | 10 | 28.5 ± 0.5 | 98.4 | 10 | 28.8 ± 0.7 | | 99.2 | 10 | 28.8 ± 0.7 | 99.4 | 10 | 27.5 ± 0.3 | 94.9 | 10 | 26.5 ± 0.4** | 91.3 | 10
42 | 30.0 ± 0.7** | 10 | 29.7 ± 0.6 | 98.8 | 10 | 30.0 ± 0.7 | | 99.7 | 10 | 29.9 ± 0.8 | 99.6 | 10 | 28.2 ± 0.3 | 94.0 | 10 | 27.3 ± 0.4** | 91.0 | 10
49 | 31.3 ± 0.7** | 10 | 31.0 ± 0.7 | 99.1 | 10 | 31.1 ± 0.8 | | 99.5 | 10 | 31.1 ± 0.8 | 99.3 | 10 | 29.3 ± 0.4 | 93.6 | 10 | 28.5 ± 0.5** | 91.2 | 10
56 | 31.9 ± 0.8** | 10 | 31.9 ± 0.8 | 99.9 | 10 | 31.9 ± 1.0 | | 100.0 | 10 | 31.7 ± 0.8 | 99.4 | 10 | 29.7 ± 0.5 | 92.9 | 10 | 29.0 ± 0.6* | 90.9 | 10
63 | 33.3 ± 1.0** | 10 | 33.3 ± 0.9 | 100.1 | 10 | 33.5 ± 1.1 | | 100.6 | 10 | 33.2 ± 0.9 | 99.8 | 10 | 30.7 ± 0.5* | 92.1 | 10 | 29.9 ± 0.7** | 89.8 | 10
70 | 34.0 ± 0.9** | 10 | 34.2 ± 1.0 | 100.6 | 10 | 34.4 ± 1.2 | | 101.4 | 10 | 33.3 ± 1.1 | 98.1 | 10 | 31.1 ± 0.6 | 91.5 | 10 | 29.9 ± 1.1** | 87.9 | 10
77 | 35.0 ± 0.9** | 10 | 35.7 ± 1.0 | 102.1 | 10 | 35.3 ± 1.2 | | 100.8 | 10 | 35.0 ± 1.1 | 100.0 | 10 | 32.2 ± 0.7 | 92.0 | 10 | 31.1 ± 0.8** | 88.8 | 10
84 | 35.8 ± 1.0** | 10 | 36.1 ± 1.1 | 100.7 | 10 | 36.1 ± 1.4 | | 100.7 | 10 | 35.9 ± 1.2 | 100.3 | 10 | 32.3 ± 0.8* | 90.3 | 10 | 31.4 ± 0.8** | 87.6 | 10
EOS^d^ | 37.2 ± 1.1** | 10 | 37.0 ± 1.1 | 99.5 | 10 | 37.2 ± 1.4 | | 100.0 | 10 | 37.2 ± 1.3 | 100.0 | 10 | 33.5 ± 0.8* | 90.1 | 10 | 32.4 ± 0.9** | 87.1 | 10

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

EOS = end of study.

^a^ Study day 0 is the day animals were placed on study.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Weights shown are mean ± standard error.

^d^ Half of the animals were euthanized on study day 91 and the other half on study day 92. Weights shown are the mean of all animals euthanized on study days 91 and 92.

Table 35 Summary of Survival and Body Weights of Female Mice in the Three-month Drinking Water Study of Vanadyl Sulfate

Study Day^a^ | 0 mg/L | | 21.0 mg/L | | | 41.9 mg/L | | | 83.8 mg/L | | | 168 mg/L | | | 335 mg/L
Study Day^a^ | Wt. (g)^b,c^ | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n | Wt. (g) | Wt. (% of Controls) | n
0 | 17.0 ± 0.3 | 10 | 17.0 ± 0.4 | 99.9 | 10 | 17.4 ± 0.3 | 102.4 | 10 | 17.1 ± 0.3 | 101.0 | 10 | 17.4 ± 0.3 | 102.5 | 10 | 17.0 ± 0.4 | 100.3 | 10
7 | 18.4 ± 0.4 | 10 | 18.2 ± 0.5 | 99.0 | 10 | 18.5 ± 0.3 | 100.3 | 10 | 18.3 ± 0.3 | 99.2 | 10 | 18.7 ± 0.3 | 101.8 | 10 | 17.1 ± 0.5 | 92.9 | 10
14 | 19.6 ± 0.5 | 10 | 19.5 ± 0.4 | 99.6 | 10 | 19.5 ± 0.4 | 99.5 | 10 | 19.3 ± 0.3 | 98.4 | 10 | 19.6 ± 0.4 | 99.8 | 10 | 18.3 ± 0.4 | 93.4 | 10
21 | 20.7 ± 0.4 | 10 | 20.4 ± 0.5 | 98.8 | 10 | 20.5 ± 0.4 | 99.2 | 10 | 20.6 ± 0.5 | 99.5 | 10 | 20.6 ± 0.4 | 99.6 | 10 | 19.3 ± 0.4 | 93.3 | 10
28 | 21.5 ± 0.6 | 10 | 21.3 ± 0.5 | 99.1 | 10 | 21.7 ± 0.6 | 100.8 | 10 | 21.3 ± 0.6 | 99.2 | 10 | 21.5 ± 0.5 | 99.8 | 10 | 20.4 ± 0.3 | 94.7 | 10
35 | 22.8 ± 0.6 | 10 | 22.0 ± 0.5 | 96.6 | 10 | 21.9 ± 0.5 | 96.1 | 10 | 22.7 ± 0.8 | 99.6 | 10 | 22.6 ± 0.5 | 99.2 | 10 | 21.1 ± 0.4 | 92.7 | 10
42 | 23.5 ± 0.8 | 10 | 23.3 ± 0.6 | 99.4 | 10 | 22.5 ± 0.5 | 95.8 | 10 | 23.1 ± 0.8 | 98.5 | 10 | 23.3 ± 0.7 | 99.4 | 10 | 21.9 ± 0.4 | 93.2 | 10
49 | 24.3 ± 0.6 | 10 | 23.9 ± 0.7 | 98.3 | 10 | 24.1 ± 0.7 | 99.3 | 10 | 24.0 ± 0.9 | 98.8 | 10 | 25.0 ± 0.9 | 103.1 | 10 | 22.6 ± 0.4 | 93.0 | 10
56 | 25.1 ± 0.6 | 10 | 24.0 ± 0.8 | 95.8 | 10 | 23.9 ± 0.5 | 95.5 | 10 | 24.8 ± 1.0 | 99.1 | 10 | 25.1 ± 1.1 | 100.0 | 10 | 23.2 ± 0.5 | 92.7 | 10
63 | 25.8 ± 1.1 | 10 | 25.7 ± 0.8 | 99.6 | 10 | 26.0 ± 0.8 | 100.5 | 10 | 25.7 ± 1.1 | 99.3 | 10 | 26.4 ± 1.1 | 102.1 | 10 | 24.3 ± 0.6 | 93.8 | 10
70 | 26.8 ± 0.9 | 10 | 26.7 ± 0.8 | 99.3 | 10 | 26.9 ± 0.8 | 100.1 | 10 | 27.3 ± 1.3 | 101.6 | 10 | 27.7 ± 1.1 | 103.1 | 10 | 24.6 ± 0.5 | 91.5 | 10
77 | 27.3 ± 1.0 | 10 | 26.7 ± 1.0 | 97.6 | 10 | 27.4 ± 1.0 | 100.1 | 10 | 27.4 ± 1.3 | 100.2 | 10 | 27.7 ± 1.3 | 101.1 | 10 | 24.7 ± 0.5 | 90.5 | 10
84 | 27.2 ± 1.2 | 10 | 27.4 ± 1.1 | 100.9 | 10 | 27.6 ± 1.1 | 101.5 | 10 | 27.2 ± 1.2 | 100.1 | 10 | 28.2 ± 1.3 | 103.6 | 10 | 25.2 ± 0.6 | 92.6 | 10
91 | 27.7 ± 1.2 | 10 | 29.0 ± 1.1 | 104.6 | 10 | 29.2 ± 1.0 | 105.2 | 10 | 28.1 ± 1.2 | 101.4 | 10 | 28.8 ± 1.2 | 104.1 | 10 | 25.3 ± 0.6 | 91.4 | 10

^a^ Study day 0 is the day animals were placed on study.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ Weights shown are mean ± standard error.

Figure 5

Growth Curves for Male and Female Mice in the Three-month Drinking Water Study of Vanadyl Sulfate

Growth curves are shown for (A) males and (B) females.

In males, water consumption over the study duration (study day 0–91) in the 335 mg/L group was 10% lower than the control group; all other exposed groups were similar to the control group. In females, water consumption over the study duration by all exposed groups was significantly decreased (10% to 17% lower than the control group) and exhibited a negative trend but was considered similar to the control group (i.e., no strong concentration response). Vanadyl sulfate intake over the course of the study (study day 0–91) is presented in Table 36.

Table 36 Summary of Water and Vanadyl Sulfate Consumption by Male and Female Mice in the Three-month Drinking Water Study

Study Day^a^ | 0 mg/L | 21.0 mg/L | 41.9 mg/L | 83.8 mg/L | 168 mg/L | 335 mg/L
Male (g/kg/day)^b^
0–7 | 143.8 ± 3.9**(10) | 135.8 ± 4.0 (10) | 141.0 ± 3.1 (10) | 138.0 ± 3.9 (10) | 139.4 ± 4.9 (10) | 109.5 ± 3.3** (10)
21–28 | 129.1 ± 5.3* (10) | 120.1 ± 2.8 (10) | 131.0 ± 5.9 (10) | 124.2 ± 2.6 (10) | 125.7 ± 3.9 (10) | 107.7 ± 2.5** (10)
84–91 | 98.7 ± 4.7 (10) | 91.3 ± 4.1 (10) | 96.8 ± 5.6 (10) | 97.3 ± 4.1 (10) | 107.5 ± 3.5 (10) | 99.3 ± 3.3 (10)
0–91 | 114.5 ± 3.3 (10) | 111.2 ± 3.2 (10) | 115.1 ± 3.6 (10) | 113.7 ± 3.1 (10) | 119.0 ± 2.7 (10) | 102.6 ± 2.5 (10)
Chemical Intake (mg/kg/day)^c,d^
0–91 | 0.0 ± 0.0 (10) | 2.3 ± 0.1 (10) | 4.8 ± 0.2 (10) | 9.5 ± 0.3 (10) | 20.0 ± 0.5 (10) | 34.4 ± 0.8 (10)
Female (g/kg/day)
0–7 | 134.1 ± 3.7**(10) | 110.7 ± 2.9** (10) | 110.8 ± 2.3** (10) | 114.2 ± 3.0** (10) | 104.8 ± 4.8** (10) | 71.7 ± 1.9** (10)
21–28 | 135.4 ± 2.9**(10) | 118.6 ± 3.9** (10) | 118.9 ± 3.0** (10) | 105.7 ± 2.1** (10) | 114.9 ± 2.1** (10) | 100.2 ± 1.6** (10)
84–91 | 97.7 ± 4.2 (10) | 91.0 ± 3.2 (10) | 83.8 ± 3.2* (10) | 91.9 ± 3.5 (10) | 87.1 ± 3.7 (10) | 95.0 ± 2.1 (10)
0–91 | 119.3 ± 3.4**(10) | 107.4 ± 3.0* (10) | 103.5 ± 2.8** (10) | 99.6 ± 2.7** (10) | 101.8 ± 2.8** (10) | 102.9 ± 2.0** (10)
Chemical Intake (mg/kg/day)
0–91 | 0.0 ± 0.0 (10) | 2.3 ± 0.1 (10) | 4.3 ± 0.1 (10) | 8.3 ± 0.2 (10) | 17.1 ± 0.5 (10) | 34.5 ± 0.7 (10)

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error (number of animals).

^b^ Each exposed group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^c^ Chemical intake calculated as: ([exposure concentration × water consumption]/[average body weight of day range]).

^d^ No statistical analysis was performed on the chemical intake data.

Several significant relative organ weight changes were observed, but these were not considered toxicologically relevant (Appendix E).

Reticulocyte count was significantly increased in the 335 mg/L male group (Table 37). In both male and female mice, MCV was significantly decreased in the ≥168 mg/L groups; the decreases in MCV indicated microcytosis. Additionally, in male mice, hemoglobin was significantly decreased in the 335 mg/L group, MCH was significantly decreased in the ≥83.8 mg/L groups, and MCHC was significantly decreased in the ≥168 mg/L groups. In female mice, erythrocyte count was significantly increased in the ≥83.8 mg/L groups, MCH was significantly decreased in the ≥83.8 mg/L groups, and MCHC was significantly decreased in the ≥168 mg/L groups.

Table 37 Summary of Select Hematology Data for Male and Female Mice in the Three-month Drinking Water Study of Vanadyl Sulfate

Endpoint^a,b^ | 0 mg/L | 21.0 mg/L | 41.9 mg/L | 83.8 mg/L | 168 mg/L | 335 mg/L
Male
n | 10 | 9 | 9 | 9 | 9 | 10
Hemoglobin (g/dL) | 15.4 ± 0.2** | 15.4 ± 0.1 | 15.4 ± 0.1 | 15.1 ± 0.1 | 15.0 ± 0.1 | 14.6 ± 0.1**
Erythrocytes (10^6^/µL) | 10.60 ± 0.12* | 10.44 ± 0.19 | 10.68 ± 0.08 | 10.58 ± 0.12 | 10.79 ± 0.14 | 10.98 ± 0.10
Reticulocytes (10^3^/µL) | 265.8 ± 5.1** | 264.2 ± 8.7 | 274.6 ± 9.4 | 276.8 ± 9.4 | 272.5 ± 8.7 | 302.0 ± 7.0**^c^
Mean Cell Volume (fL) | 49.6 ± 0.2** | 50.2 ± 0.3 | 49.5 ± 0.2 | 49.1 ± 0.2 | 48.6 ± 0.3* | 47.0 ± 0.3**
Mean Cell Hemoglobin (pg) | 14.5 ± 0.1** | 14.8 ± 0.2 | 14.4 ± 0.1 | 14.3 ± 0.1* | 13.9 ± 0.1** | 13.3 ± 0.1**
Mean Cell Hemoglobin Concentration (g/dL) | 29.3 ± 0.2** | 29.5 ± 0.5 | 29.1 ± 0.1 | 29.0 ± 0.2 | 28.7 ± 0.1** | 28.4 ± 0.2**
Female
n | 9 | 9 | 10 | 10 | 10 | 9
Hemoglobin (g/dL) | 15.1 ± 0.1 | 15.0 ± 0.1 | 13.7 ± 1.3 | 15.3 ± 0.1 | 15.0 ± 0.2 | 14.4 ± 0.2
Erythrocytes (10^6^/µL) | 10.14 ± 0.09** | 9.30 ± 0.98 | 9.28 ± 0.94 | 10.51 ± 0.06* | 10.61 ± 0.12** | 10.75 ± 0.13**
Reticulocytes (10^3^/µL) | 264.6 ± 21.6 | 261.7 ± 29.9 | 254.4 ± 32.5 | 303.2 ± 28.1 | 276.7 ± 11.5 | 251.4 ± 14.0
Mean Cell Volume (fL) | 50.0 ± 0.3** | 50.0 ± 0.2 | 49.4 ± 0.3 | 49.3 ± 0.2 | 48.3 ± 0.2** | 46.7 ± 0.3**
Mean Cell Hemoglobin (pg) | 14.9 ± 0.1** | 23.7 ± 9.0 | 15.7 ± 1.0 | 14.6 ± 0.1* | 14.1 ± 0.1** | 13.4 ± 0.1**
Mean Cell Hemoglobin Concentration (g/dL) | 29.8 ± 0.2** | 47.7 ± 18.4 | 31.8 ± 2.0 | 29.6 ± 0.2 | 29.2 ± 0.1* | 28.8 ± 0.1**

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ n = 9. One sample in the indicated group was excluded from analysis due to biological implausibility.

In male mice, there were no vanadyl sulfate-related changes in sperm counts or motility parameters (Appendix E). In female mice, there was no effect of vanadyl sulfate on the number of estrous cycles or cycle length. Markov model estimates of stage length indicated a significant decrease in metestrus stage length (0.3 days) in the 168 mg/L group and a significant decrease in estrus stage length (0.4 days) in the 335 mg/L group relative to the control group. There were no corresponding changes to the other cycle stages (Appendix E). Given the minimal response and absence of an exposure concentration response, these findings are likely spurious.

##### Histopathology

This section describes the statistically significant or biologically noteworthy changes in the incidence of nonneoplastic lesions in the small intestine.

Small intestine: In male and female mice exposed to vanadyl sulfate, hyperplasia of the epithelium was observed in the ileum and jejunum of the small intestine; however, this lesion was not observed in the large intestine (Table 38). As with the other studies, the lesion was most prevalent in the ileum, followed by the jejunum. In males, epithelial hyperplasia was seen in the ileum in the ≥83.8 mg/L groups, with a positive trend and a significant pairwise comparison in the 335 mg/L group. In the jejunum, this lesion was seen in only one male in the 335 mg/L group. In females, epithelial hyperplasia of the ileum was observed in the ≥83.8 mg/L groups, with a positive trend and significant pairwise comparisons in the ≥168 mg/L groups. In the jejunum, epithelial hyperplasia was seen in the ≥168 mg/L groups, with a positive trend. In all applicable cases, the severity of the lesion increased with increasing exposure concentration. Incidences of epithelial hyperplasia were observed in all intestinal sites (combined) in males and females exposed to ≥83.8 mg/L, with a positive trend and significant pairwise comparisons in the 335 mg/L male group and the ≥168 mg/L female groups. This lesion was not observed in males and females exposed to ≤41.9 mg/L. Epithelial hyperplasia occurred in the ileum in all animals in the 335 mg/L groups, with the exception of one male. The histological appearance of this lesion was identical to that described in rats exposed to sodium metavanadate (see Sodium Metavanadate Rat Histopathology).

Table 38 Incidences of Epithelial Hyperplasia of the Small Intestine in Male and Female Mice in the Three-month Drinking Water Study of Vanadyl Sulfate

| 0 mg/L | 21.0 mg/L | 41.9 mg/L | 83.8 mg/L | 168 mg/L | 335 mg/L
Male
n^a^ | 10 | 0 | 9 | 9 | 10^b^ | 10
Intestine, Small, Ileum
Epithelium, hyperplasia^c^ | 0** | –^d^ | 0 | 2 (1.0)^e^ | 3 (1.3) | 9** (1.9)
Intestine, Small, Jejunum
Epithelium, hyperplasia | 0 | – | – | – | 0 | 1 (2.0)
Intestine, Any Site
Epithelium, hyperplasia | 0** | – | 0 | 2 | 3 | 9**
Female
n | 10 | 0 | 10 | 10^b^ | 10 | 10
Intestine, Small, Ileum
Epithelium, hyperplasia | 0** | – | 0 | 1 (1.0) | 5* (1.4) | 10** (1.9)
Intestine, Small, Jejunum
Epithelium, hyperplasia | 0* | – | 0 | 0 | 1 (1.0) | 2 (2.0)
Intestine, Any Site | 10
Epithelium, hyperplasia | 0** | – | 0 | 1 | 5* | 10**

Statistical significance for an exposed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ For the small intestine, ileum data, n =9 for the male 168 mg/L group and the female 83.8 mg/L group.

^c^ Number of animals with lesion. Statistical analyses performed by Cochran-Armitage (trend) and Fisher’s exact (pairwise) one-sided tests.

^d^ Data were not collected for an exposed group when animals exposed to higher concentrations exhibited no incidences of nonneoplastic lesions in that tissue.

^e^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

## Genetic Toxicology

Data from all NTP genetic toxicity tests with sodium metavanadate and vanadyl sulfate are available in the NTP Chemical Effects in Biological Systems database: https://doi.org/10.22427/NTP-DATA-TOX-106.

The genetic toxicity of sodium metavanadate and vanadyl sulfate was evaluated in bacterial reverse mutation and in rat and mouse peripheral blood micronucleus assays.

### Bacterial Mutation Studies

Neither sodium metavanadate nor vanadyl sulfate was mutagenic in Salmonella typhimurium strains TA98 and TA100 or in Escherichia coli strain WP2 uvrA (pKM101) in tests conducted with and without exogenous metabolic activation provided by phenobarbital/benzoflavone-induced male rat liver S9 and cofactors (Table D-1, Table D-2). Sodium metavanadate was tested at concentrations of 0.5–100 µg/plate in TA98 with or without S9 mix and in TA100 at concentrations of 0.5–100 µg/plate without S9 mix and 1.0–500 µg/plate with S9 mix. For TA98 and TA100, the top concentration was limited by cytotoxicity. In E. coli, sodium metavanadate was tested at concentrations of 40–6,000 µg/plate with or without S9 mix. Vanadyl sulfate was tested at concentrations of 0.4–100 µg/plate in TA98 and TA100 with or without S9 mix. For TA98, the top concentration was limited by cytotoxicity. In E. coli, vanadyl sulfate was tested at concentrations of 4.0–6,000 µg/plate with or without S9 mix.

### In Vivo Peripheral Blood Micronucleus Test

At the end of the 3-month studies of sodium metavanadate and vanadyl sulfate, peripheral blood samples were obtained from male and female rats and mice and analyzed for the frequency of micronucleated immature erythrocytes (i.e., reticulocytes or polychromatic erythrocytes [PCEs]) and mature erythrocytes (i.e., normochromatic erythrocytes [NCEs]). In male and female rats, the reticulocyte population is the only red blood cell population that can be accurately assessed for micronucleus frequency in peripheral blood of rats due to efficient splenic scavenging of damaged erythrocytes.

In the sodium metavanadate study, a significant trend test was observed for the frequency of micronucleated reticulocytes in male rats, meeting statistical criteria for an equivocal result (Table D-3). However, the frequencies of micronucleated reticulocytes for the control group and all groups exposed to sodium metavanadate were well within the laboratory historical vehicle control (mean ± 2 standard deviations, or 95% confidence interval); therefore, this result was judged to be negative. Significant increases in the percentage of reticulocytes were observed in male rats, indicating that exposure to sodium metavanadate had a stimulatory effect on erythropoiesis. No increases in the frequencies of micronucleated reticulocytes were observed in female rats after 3 months of exposure to sodium metavanadate via drinking water. No increases in the frequencies of micronucleated reticulocytes or micronucleated mature erythrocytes were observed in male or female mice exposed to sodium metavanadate in drinking water for 3 months (Table D-4). However, significant increases in the percentage of reticulocytes were observed for both male and female mice, indicating that exposure to sodium metavanadate had a stimulatory effect on erythropoiesis.

In the vanadyl sulfate study, male and female rats did not show an increase in micronucleated reticulocytes (Table D-5). No significant changes in the percentage of reticulocytes were observed for male or female rats, suggesting that vanadyl sulfate exposure did not affect erythropoiesis. No significant increases in the frequencies of micronucleated reticulocytes or micronucleated mature erythrocytes were observed in male or female mice administered vanadyl sulfate in drinking water for 3 months (Table D-6). However, significant increases in the percentage of reticulocytes were observed for male and female mice, indicating that exposure to vanadyl sulfate had a stimulatory effect on erythropoiesis.