# Materials and Methods

## Procurement and Characterization of Sodium Metavanadate and Vanadyl Sulfate

Sodium metavanadate was obtained from MP Biomedicals (Irvine, CA) in a single lot (8579K). Vanadyl sulfate was obtained from Noah Technologies Corporation (San Antonio, TX) in a single lot (0210324/1.1). The manufacturer’s certificate of analysis for vanadyl sulfate listed the material as vanadyl sulfate hydrate with an unspecified number of water molecules (VOSO_4_·xH_2_O) but provided the CASRN for the anhydrous form. The chemical name vanadyl sulfate and the corresponding CASRN 27774-13-6 were used for the purpose of reporting the study. Identity, purity, and stability analyses were conducted at the Battelle analytical chemistry laboratory (Columbus, OH) (Appendix A). Reports on analyses performed in support of the sodium metavanadate and vanadyl sulfate studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

Lot 8579K of sodium metavanadate (a white-to-yellow powder) and lot 0210324/1.1 of vanadyl sulfate (a blue powder) were identified as sodium metavanadate and a hydrated form of vanadyl sulfate, respectively, using infrared spectroscopy and X-ray diffraction.

Moisture content was determined by weight loss on drying, Karl Fischer titration, and thermal gravimetric analysis (TGA). Karl Fischer titration was conducted by Galbraith Laboratories, Inc. (Knoxville, TN). For lot 8579K of sodium metavanadate, water content was measured at 0.2% by weight loss on drying, 0.16% by Karl Fischer titration, and 0.25% by TGA. For lot 0210324/1.1 of vanadyl sulfate, water content was measured at 21.8% by weight loss on drying, 22.8% by Karl Fischer titration, and 32.9% by TGA. The quantity of water measured by TGA was likely a more accurate estimate because it measures both crystalline and latent water, whereas weight loss on drying and Karl Fischer titration measured only adsorbed water. Overall, lot 0120324/1.1 of vanadyl sulfate was determined to be 33% water and 67% vanadyl sulfate.

Elemental analysis on both test articles was performed by scanning electron microscope energy dispersive X-ray spectroscopy, proton-induced X-ray emission (PIXE) spectroscopy, and inductively coupled plasma atomic emission spectroscopy. The PIXE analyses were conducted by Elemental Analysis, Inc. (Lexington, KY). Overall, the elemental compositions were close to the theoretical values for sodium metavanadate and vanadyl sulfate, and no major impurities were detected.

Lot 8579K of sodium metavanadate and lot 0210324/1.1 of vanadyl sulfate were analyzed using high-performance liquid chromatography (HPLC) with charged aerosol detection (CAD) (Table A-1). No impurities were detected using HPLC/CAD. The volatile content was determined by gas chromatography with flame ionization detection and electron capture detection (Table A-2). No volatiles were detected. The overall purity of both chemicals was determined to be >99%. The analytical methods and systems used for each respective lot are described in detail in Appendix A.

Accelerated stability studies confirmed the bulk chemicals were stable for at least 2 weeks when stored at temperatures of ≤60°C in sealed containers protected from light. Bulk sodium metavanadate was stored in amber plastic bottles at room temperature, and bulk vanadyl sulfate was stored in white plastic containers at room temperature. Periodic reanalyses of the bulk chemicals were performed by the analytical chemistry laboratory before, during, and after the studies, using HPLC/CAD, and no degradation of either bulk chemical was detected.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared monthly at the Battelle study laboratory (West Jefferson, OH) by mixing sodium metavanadate or vanadyl sulfate with American Society for Testing and Materials (ASTM) Type I water, adjusted to pH 6 to 8 or pH 3.5, respectively, to give the required concentrations (Table A-3, Table A-4). Dose formulations of sodium metavanadate were prepared at six concentrations of 0, 31.3, 62.5, 125, 250, and 500 mg/L. Dose formulations of vanadyl sulfate were prepared at six concentrations of 0, 21.0, 41.9, 83.8, 168, and 335 mg/L (after being corrected for 33% water content). The formulations were prepared five times for the rat studies and three times for the mouse studies. During formulation development work, a small peak corresponding to the retention time of vanadate (V^5+^) was observed in vanadyl sulfate formulations; the absolute amount of conversion was similar regardless of the concentration and did not increase with time.^37^ The storage stability was confirmed at refrigerated and room temperatures when protected from light for up to 42 days. All dose formulations were stored at the study laboratory in plastic carboys at refrigerated temperatures (2°C–8°C) and were used within 42 days of preparation (Appendix A).

Analysis of preadministration and postadministration (animal room) dose formulations were conducted monthly at the study laboratory. All preadministration dose formulations for sodium metavanadate (Table A-5, Table A-6) were within 10% of the target concentrations. All postadministration samples were within 10% of the target concentrations, except for two animal room samples for the rat study, which were 11.7% and 10.9% below the target concentrations. All preadministration dose formulations for vanadyl sulfate (Table A-7, Table A-8) were within 10% of the target concentrations. All postadministration samples were within 10% of target concentrations, except for one animal room sample for the rat study, which was 13.7% below the target concentration.

## Animal Source

Time-mated (F_0_) female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were obtained from Envigo (formerly Harlan Laboratories, Inc., Haslett, MI). Male and female B6C3F1/N mice were obtained from the National Toxicology Program (NTP) colony maintained by Taconic Biosciences, Inc. (Germantown, NY).

## Animal Welfare

Animal care and use were in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the Battelle (Columbus, OH) Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Exposure Selection Rationale

Test article concentrations in drinking water for these studies were selected based on previous 14-day drinking water studies.^2,3^ The highest exposure concentrations were selected based on the magnitude of reduced water consumption, lower body weight effects, and clinical observations at concentrations higher than 500 mg/L (sodium metavanadate) and 335 mg/L (vanadyl sulfate). The test compound concentrations and the calculated vanadium concentrations are shown in Table 2.

Table 2 Concentrations of Sodium Metavanadate, Vanadyl Sulfate, and Vanadium in the Three-month Drinking Water Studies

Sodium Metavanadate | | Vanadyl Sulfate
Test Article (mg/L) | Vanadium^a^ (mg/L) | Test Article (mg/L) | Vanadium^b^ (mg/L)
0 | 0 | 0 | 0
31.3 | 13.1 | 21.0 | 6.5
62.5 | 26.1 | 41.9 | 13
125 | 52.1 | 83.8 | 26
250 | 104.3 | 168 | 52.1
500 | 208.5 | 335 | 103.9

^a^ Based on vanadium composition in sodium metavanadate of 41.7%.

^b^ Based on vanadium composition in vanadyl sulfate of 31%.

## Three-month Studies

### Study Design for Rats

F_0_ female Sprague Dawley rats were 11 to 14 weeks old (sodium metavanadate) or 12 to 13 weeks old (vanadyl sulfate) upon receipt. Gestation day (GD) 1 was defined as the first day with evidence of mating; F_0_ females were received on GD 2 and held for 4 days. F_0_ females were randomly assigned to one of six exposure groups for both sodium metavanadate and vanadyl sulfate on GD 5. Randomization was stratified by body weight to produce similar group mean weights using NTP Provantis software (Instem, Stone, UK).

F_0_ female rats were quarantined for 12 days (sodium metavanadate) or 14 days (vanadyl sulfate) after receipt. Ten nonmated female rats received in the same shipment as the time-mated dams were designated for disease monitoring and were used for gross necropsies 2 days after arrival; samples were collected for parasite evaluation and gross observation of disease. The health of the F_1_ animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Beginning on GD 6, groups of 16 F_0_ female rats were administered sodium metavanadate or vanadyl sulfate in drinking water (ASTM Type I water, adjusted to a pH of approximately 7 for sodium metavanadate and 3.5 for vanadyl sulfate) throughout gestation and lactation at the following exposure concentrations: sodium metavanadate (0, 31.3, 62.5, 125, 250, or 500 mg/L) or vanadyl sulfate (0, 21.0, 41.9, 83.8, 168, or 335 mg/L). Vehicle control animals were administered drinking water alone (ASTM Type I water, adjusted to a pH of approximately 7 for sodium metavanadate and 3.5 for vanadyl sulfate).

Feed and dosed water were available ad libitum. F_0_ females were housed individually during gestation and with their respective litters during lactation. Cages were changed weekly for pregnant dams before delivery and twice weekly for dams and their litters after postnatal day (PND) 4. F_0_ females were observed twice daily for signs of mortality or moribundity. Body weights were recorded upon receipt on GD 3 (vanadyl sulfate), on GD 5 (for randomization), and on GDs 6, 9, 12, 15, 18, and 21. Clinical observations were recorded daily from GD 6 through GD 21. Water consumption data were recorded on GDs 6, 9, 12, 15, 18, and 21. Details of the study design and animal maintenance are summarized in Table 3.

Table 3 Experimental Design and Materials and Methods in the Three-month Studies of Sodium Metavanadate and Vanadyl Sulfate

Rats | Mice
Study Laboratory
Battelle (Columbus, OH) | Same as in rats
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) | B6C3F1/N
Animal Source
Envigo (formerly Harlan Laboratories, Inc., Haslett, MI) | Taconic Biosciences, Inc. (Germantown, NY)
Time Held Before Studies
Sodium metavanadate: 4 days Vanadyl sulfate: 4 days | Sodium metavanadate: 11 days Vanadyl sulfate: 12 days
Average Age When Studies Began
F_0_ females (sodium metavanadate): 11–15 weeks F_0_ females (vanadyl sulfate): 12–14 weeks | 6 weeks
Date of First Exposure
F_0_ females (sodium metavanadate): February 12, 2016 F_0_ females (vanadyl sulfate): May 1, 2016 F_1_ rats (sodium metavanadate): March 27–28, 2016 F_1_ rats (vanadyl sulfate): June 13–15, 2016 | Sodium metavanadate: January 25 (females) or 26 (males), 2016 Vanadyl sulfate: April 11 (females) or 12 (males), 2016
Duration of Exposure
F_0_ females: GD 6 through LD 28 F_1_ rats: Perinatal plus 3 months | 3 months
Date of Last Exposure
F_0_ females (sodium metavanadate): March 27–28, 2016 F_0_ females (vanadyl sulfate): June 13–15, 2016 F_1_ rats (sodium metavanadate): June 27–29, 2016 F_1_ rats (vanadyl sulfate): September 12–16, 2016 | Sodium metavanadate: April 25 (females) or 26 (males), 2016 Vanadyl sulfate: July 11 (females) or 13 (males), 2016
Necropsy Dates
F_1_ rats (sodium metavanadate): June 27–29, 2016 F_1_ rats (vanadyl sulfate): September 14–16, 2016 | Sodium metavanadate: April 25–26, 2016 Vanadyl sulfate: July 11–13, 2016
Average Age at Necropsy
F_1_ rats: 17 weeks | 19 weeks
Size of Study Groups
F_0_ females: 16/group F_1_ rats (interim evaluation): 20/sex/group F_1_ rats (core study): 10/sex/group F_1_ rats (investigative study): 5/sex/group | 10/sex/group
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights using NTP Provantis (Instem, Stone, UK). | Same as in rats
Animals per Cage
F_0_ females: 1 (with litter) F_1_ rats: up to 2 (males) or up to 4 (females) | 1 (males) or up to 5 (females)
Method of Animal Identification
F_0_ females: Cage card and tail marking | Cage card and tail tattoo
F_1_ rats: Limb tattoo until PND 28, then cage card and tail mark/tattoo
Diet
F_0_ females: Irradiated NIH-07 wafer feed (Zeigler Brothers, Gardners, PA), available ad libitum, changed at least weekly | Irradiated NTP-2000 wafer feed (Zeigler Brothers, Gardners, PA), available ad libitum, changed at least weekly
F_1_ rats: Irradiated NTP-2000 wafer feed (Zeigler Brothers, Gardners, PA), available ad libitum, changed at least weekly
Water
ASTM Type I water (adjusted to a pH of ~7 for sodium metavanadate and 3.5 for vanadyl sulfate), either untreated or containing a formulation of sodium metavanadate or vanadyl sulfate via water bottles, available ad libitum | Same as in rats
Cages
Solid polycarbonate (Lab Products, Inc., Seaford, DE), changed at least weekly (individually housed F_0_ females and their litters through PND 4) or twice weekly (group-housed rats). After PND 28, cage rotation occurred at least every 2 weeks. | Solid polycarbonate (Lab Products, Inc., Seaford, DE), changed at least weekly and rotated at least every 2 weeks
Bedding
Irradiated Sani-Chips^®^ (P.J. Murphy Forest Products Corporation, Montville, NJ), changed with cage changes | Same as in rats
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed and rotated every 2 weeks | Same as in rats
Rack Filters
Spun-bonded polyester (National Filter Media Corporation, Olive Branch, MS), changed every 2 weeks | Same as in rats
Animal Room Environment
Temperature: 70°F–73°F Relative humidity: 28%–65% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Temperature: 67°F–74°F Relative humidity: 28%–60% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour
Exposure Concentrations
Sodium metavanadate: 0, 31.3, 62.5, 125, 250, or 500 mg/L in drinking water | Same as in rats
Vanadyl sulfate: 0, 21.0, 41.9, 83.8, 168, or 335 mg/L in drinking water
Type and Frequency of Observation
F_0_ females: Observed twice daily. Weighed on GDs 3 (vanadyl sulfate), 5, 6, 9, 12, 15, 18, and 21 and on LDs 1, 4, 7, 10, 13, 16, 19, 21, 25, and 28. Water consumption was measured on GDs 6, 9, 12, 15, 18, and 21 and on LDs 1, 4, 7, 10, 13, 16, 19, 21, 24 (sodium metavanadate), 25, and 28. Clinical observations were recorded daily from GD 6 through LD 28. | Observed twice daily. Weighed at randomization, prior to exposure on day 1, weekly thereafter, and at study termination. Clinical observations were recorded weekly. Water consumption was reported weekly.
F_1_ rats: Observed twice daily. Litter weights by sex were recorded on PND 1. The number and sex of pups were recorded daily throughout the lactation period. Pups were weighed individually on PNDs 4, 7, 10, 13, 16, 19, 21, 25, and 28, weekly thereafter, and at study termination. Clinical observations were recorded from PND 4 through PND 28, weekly thereafter, and at study termination. Water consumption was recorded weekly. Vaginal opening (and concomitant body weight) was evaluated beginning on PND 25, and balanopreputial separation (and concomitant body weight) was evaluated beginning on PND 35.
Method of Euthanasia
F_0_ females and F_1_ internal dose assessment rats: carbon dioxide and/or exsanguination | Carbon dioxide
F_1_ core study rats: carbon dioxide
Necropsy
F_1_ core study rats: Complete necropsies were performed on all animals. Organs weighed at study termination were left and right epididymis, heart, left and right kidney, liver, lungs, left and right ovary, left and right testis, and thymus. | Same as in rats
Clinical Pathology
Following perinatal exposure on PND 28 (interim evaluation rats) and at study termination (core study rats), blood was collected from the retroorbital plexus for hematology, clinical chemistry (core study rats), and erythrocyte micronuclei (core study rats). | At study termination, blood was collected from the retroorbital sinus for hematology and erythrocyte micronuclei.
Hematology: hematocrit; manual hematocrit; hemoglobin concentration; red blood cell, nucleated red blood cell, reticulocyte, and platelet counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; white blood cell count and differential; morphological evaluation | Same as in rats
Clinical chemistry: urea nitrogen, creatinine, glucose, total protein, albumin, globulin, A/G ratio, cholesterol, triglycerides, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, total bile acids | None
Histopathology
F_1_ core study: Complete histopathology was performed to a no-effect level, plus on all animals in the control groups. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal glands, brain (seven sections including [1] olfactory bulbs, [2] fronto-parietal cortex and basal ganglia, [3] mid-parietal cortex and thalamus, [4] mid-brain with substantia nigra and red nucleus, [5] posterior colliculi, [6] mid-cerebellum including cranial nerve VIII, and [7] posterior medulla), cervix/vagina, clitoral glands, esophagus, eyes, femur (including diaphysis with marrow cavity and epiphysis [femoral condyle with epiphyseal cartilage plate, articular cartilage, and articular surface]), Harderian glands, heart and aorta, kidneys, large intestine (cecum, colon, rectum), liver (two sections including left lateral lobe and median lobe), lungs and mainstem bronchi, lymph nodes (mandibular and mesenteric), mammary gland with adjacent (inguinal) skin, muscle (thigh), nasal cavity and nasal turbinates, nerve (sciatic, tibial, and trigeminal with ganglion), ovaries, pancreas, parathyroid glands, pituitary gland, preputial glands, prostate, salivary glands, seminal vesicle, small intestine (duodenum, jejunum, ileum), spinal cord, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus. | Complete histopathology was performed to a no-effect level, plus on all animals in the control groups. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, brain (seven sections including [1] olfactory bulbs, [2] fronto-parietal cortex and basal ganglia, [3] mid-parietal cortex and thalamus, [4] mid-brain with substantia nigra and red nucleus, [5] posterior colliculi, [6] mid-cerebellum including cranial nerve VIII, and [7] posterior medulla), cervix/vagina, clitoral glands, esophagus, eyes, femur (including diaphysis with marrow cavity and epiphysis [femoral condyle with epiphyseal cartilage plate, articular cartilage, and articular surface]), gallbladder, Harderian glands, heart and aorta, kidneys, large intestine (cecum, colon, rectum), liver (two sections including left lateral lobe and median lobe), lungs and mainstem bronchi, lymph nodes (mandibular and mesenteric), mammary gland, muscle (thigh) (sodium metavanadate), nasal cavity and nasal turbinates, nerve (sciatic and trigeminal with ganglion), ovaries, pancreas, parathyroid glands, pituitary glands, preputial glands, prostate gland, salivary glands, seminal vesicle, small intestine (duodenum, jejunum, ileum), spinal cord, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus.
Sperm Motility and Vaginal Cytology
F_1_ core study rats: At study termination, sperm samples were collected from male rats in the 0, 125, 250, and 500 mg/L (sodium metavanadate) groups and in the 0, 83.8, 168, and 335 mg/L (vanadyl sulfate) groups for sperm count and sperm motility evaluations. The cauda epididymis was weighed. Vaginal samples were collected for up to 16 consecutive days before study termination from female rats in the 0, 125, 250, and 500 mg/L (sodium metavanadate) groups and in the 0, 83.8, 168, and 335 mg/L (vanadyl sulfate) groups for vaginal cytology evaluations. | Same as in rats
F_1_ Investigative Study
Excretion and internal dose assessment: At study termination, urine and plasma were collected for chemical analysis. For urine collection, animals were placed in metabolism cages and given control (0 mg/L) drinking water, and urine was collected over a 24-hour period. Plasma was then collected within 2 hours of lights-on, and all samples were collected within 2.5 hours. Results of the plasma and urine analyses have been reported previously.^40^ | None
Urinalysis: At study termination, urine samples were collected as described above and analyzed for appearance, volume, specific gravity, microscopic assessment, total protein, glucose, creatinine, calcium, phosphorus, N-acetyl-β-glucosaminidase, alkaline phosphatase, and aspartate aminotransferase. | None
Comet assay: At study termination, samples of liver, duodenum, and colon epithelium were collected for the comet assay. Due to sample quality and analysis issues, comet assay data were not analyzed or reported. | At study termination, samples of liver and duodenum were collected for the comet assay. Due to sample quality and analysis issues, comet assay data were not analyzed or reported.

GD = gestation day; LD = lactation day; PND = postnatal day.

The day of parturition was considered lactation day (LD) 0 for dams and PND 0 for pups. F_0_ females that did not deliver were euthanized on GD 27, and the uteri were examined for evidence of implantation and resorption. Body weights of littered F_0_ females were recorded on LDs 1, 4, 7, 10, 13, 16, 19, 21, 25, and 28. Water consumption data were recorded on LDs 1, 4, 7, 10, 13, 16, 19, 21, 24 (sodium metavanadate only), 25, and 28. Clinical observations were recorded daily from LD 1 through LD 28. From PND 0 through PND 28, the number and sex of pups for each litter were recorded daily. On PND 1, litter weights by sex were recorded. Litter observations were recorded daily from PND 1 through PND 3, and clinical observations were recorded daily from PND 4 through PND 28. F_1_ pups were individually weighed on PNDs 4, 7, 10, 13, 16, 19, 21, 25, and 28.

On PND 4, the litters were standardized to eight pups per litter (four males and four females when possible). Weaning occurred on PND 28. One male and one female from 10 litters per exposure group were randomly selected for use in the 3-month study; all available pups (n = 12 [female] or 13 [male] from four litters) were retained in the 500 mg/L sodium metavanadate study. Five pups per sex representing five litters per exposure group (except for the 500 mg/L group) were randomly selected for investigative study assessments. Two pups per sex were randomly selected from 10 litters per exposure group for an interim hematology assessment at PND 28. Five additional pups per sex (from control litters) were designated for disease monitoring. Following weaning, all F_0_ females and unselected pups were humanely euthanized with carbon dioxide. Weaning marked the beginning of the 3-month study.

Groups of 10 male and 10 female F_1_ pups were administered 0, 31.3, 62.5, 125, 250, or 500 mg/L sodium metavanadate or 0, 21.0, 41.9, 83.8, 168, or 335 mg/L vanadyl sulfate in drinking water for 3 months, starting on PND 28. A separate group of five male and five female F_1_ pups selected for the investigative study was administered the same concentrations for internal dose assessment, urinalysis, and analysis of DNA damage (i.e., comet assay). Pups were administered the same exposure that their respective dams received during gestation and lactation. Vehicle control animals were administered drinking water alone (ASTM Type I water, adjusted to a pH of approximately 7 for sodium metavanadate or 3.5 for vanadyl sulfate).

Two diets were used in the rat studies: (1) NIH-07 during the perinatal phase and (2) NTP-2000 during the postweaning phase. The NIH-07 diet is a higher protein diet that supports reproduction and lactation in rodents, whereas the NTP-2000 diet is a lower protein diet that decreases the incidence of chronic nephropathy in adult rats. F_1_ rats were housed up to two per cage for males and up to four per cage for females. Cages were changed twice weekly and rotated every 2 weeks. Details of the study design and animal maintenance are summarized in Table 3. Information on feed composition and contaminants for both diets is provided in Appendix B.

### Study Design for Mice

Male and female B6C3F1/N mice were approximately 3 to 4 weeks old upon receipt. Animals were quarantined for 11 days (sodium metavanadate) or 12 days (vanadyl sulfate), and mice were approximately 6 weeks old on the first day of the study. Mice were randomly assigned to one of six exposure groups for both sodium metavanadate and vanadyl sulfate before the start of the study. Randomization was stratified by body weight to produce similar group mean weights using NTP Provantis software (Instem, Stone, UK).

Before the studies began, five male and five female mice were randomly selected for parasite evaluation, serology, and gross observation for evidence of disease. In addition, five male and five female mice were selected for 4-week and study termination serologies and parasite evaluation. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Groups of 10 male and 10 female mice were administered 0, 31.3, 62.5, 125, 250, or 500 mg/L sodium metavanadate or 0, 21.0, 41.9, 83.8, 168, or 335 mg/L vanadyl sulfate in drinking water for 3 months. Vehicle control animals were administered drinking water alone (ASTM Type I water, adjusted to a pH of approximately 7 for sodium metavanadate or 3.5 for vanadyl sulfate). Male mice were housed individually, whereas female mice were housed up to five per cage. Cages were changed at least twice weekly and rotated at least every 2 weeks. Details of the study design and animal maintenance are summarized in Table 3. Information on feed composition and contaminants is given in Appendix B.

### Clinical Examinations and Pathology

During the 3-month studies, rats and mice were observed twice daily for signs of morbidity or moribundity. Rats were weighed, and clinical observations and water consumption were recorded on day 1, weekly thereafter, and at study termination. Mice were weighed, and clinical observations were recorded prior to exposure on day 1, weekly thereafter, and at study termination. Water consumption by mice was reported weekly for both males and females.

Attainment of balanopreputial separation (BPS), defined as complete retraction of the prepuce from the glans penis, was evaluated in all F_1_ male rats beginning on PND 35 over 21 days or until the day of attainment, and body weights were recorded upon BPS attainment. The attainment of vaginal opening (VO) was evaluated in F_1_ female rats beginning on PND 25 over 18 days (sodium metavanadate) or 19 days (vanadyl sulfate) or until the day of attainment, and the corresponding body weights were recorded upon VO attainment.

At the end of the 3-month studies, urine samples were collected over a 24-hour period for urinalysis and internal dose assessment from five male and five female rats. To collect urine, animals were placed in metabolism cages and given control (0 mg/L) drinking water, and samples were collected over a 24-hour period. Urine samples collected for chemical analysis were stored frozen in a freezer set to maintain approximately −70°C until shipped to RTI International (Research Triangle Park, NC) for analysis. Urinalysis parameters were analyzed using a Roche cobas^®^ c311 chemistry analyzer, Roche cobas u411 urine analyzer (Roche, Indianapolis, IN), and manual methods. The parameters measured are listed in Table 3.

At the end of the 3-month rat (investigative study group) and mouse studies, the liver, duodenum, and colon (rats only) were collected, weighed, and stored frozen in a freezer set to maintain a range of −85°C to −60°C until they were shipped to Integrated Laboratory Systems, LLC (ILS, Research Triangle Park, NC) for analysis of DNA damage.

Following perinatal exposure on PND 28 (interim evaluation rats) and at the end of the 3-month studies (core study rats and mice), animals were anesthetized with a carbon dioxide/oxygen mixture and bled in random order. The blood collections and necropsies for the rat and vanadyl sulfate mouse studies were staggered over 2 consecutive days to allow adequate time for sperm motility assessments to be conducted. Blood was collected from the retroorbital plexus (rats) or retroorbital sinus (mice) for hematology, clinical chemistry (core study rats), erythrocyte micronuclei analyses (core study rats and mice), and internal dose assessment. Blood for hematology, micronuclei determinations, and internal dose assessment was collected into tubes containing tripotassium ethylenediaminetetraacetic acid (K_3_ EDTA). Blood for clinical chemistry was collected into serum separator tubes and centrifuged, and the serum was harvested. Hematology parameters were analyzed using an Advia^®^ 120 hematology analyzer (Bayer Diagnostics Division, Tarrytown, NY). Clinical chemistry parameters were analyzed using a Roche cobas c311 chemistry analyzer (Roche, Indianapolis, IN). The parameters measured are listed in Table 3. Samples for erythrocyte micronuclei determination were stored at 2°C–8°C immediately after collection and shipped to Integrated Laboratory Systems, LLC (ILS, Research Triangle Park, NC) for analysis. For excretion and internal dose assessment, following 24 hours in metabolism cages for urine collection, plasma was collected within 2 hours of lights-on, and all samples were collected within 2.5 hours (Table 3). Plasma was isolated from a fraction of whole blood, and both samples were stored at −60°C to −85°C until they were shipped to RTI International for chemical analysis (Research Triangle Park, NC).

Samples were collected for sperm motility and vaginal cytology evaluations from F_1_ male and female rats and male and female mice in the 0, 125, 250, and 500 mg/L sodium metavanadate groups and in the 0, 83.8, 168, and 335 mg/L vanadyl sulfate groups. For 16 consecutive days before scheduled study termination, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were collected and subsequently stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. An incision was made in the distal region of the left cauda epididymis, and the cauda was placed in a Petri dish containing M199 solution (maintained at approximately 37°C) with 1.0% bovine serum albumin (BSA). A small sample of the diluted sperm was loaded into a 100 µm-chambered slide for determination of motility. After completion of sperm motility estimates, the remainder of the diluted sperm and cauda epididymis in M199/BSA solution and the left testis were stored frozen (approximately −70°C) until enumeration of sperm concentration was performed. The left cauda epididymis in M199/BSA solution was thawed and homogenized, and the left testis was thawed and homogenized in 0.9% saline with 0.05% Triton-X 100. Homogenized samples were mixed with a DNA-specific fluorescent dye (IDENT) to allow for sperm identification under fluorescent illumination.

Necropsies were performed on all F_1_ rats in the core study and all mice. Organ weights were determined for the left and right epididymis, heart, left and right kidney, liver, lungs, left and right ovary, left and right testis, and thymus. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes, which were first fixed in Davidson’s solution, and testis, vaginal tunics, and epididymis, which were first fixed in modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 μm, and stained with hematoxylin and eosin. Complete histopathological examinations were performed by the study laboratory pathologist on all F_1_ rats and mice to a no-effect level. Table 3 lists the tissues and organs examined.

The laboratory report and select histopathology slides were reviewed by quality assessment (QA) pathologists, who also served as coordinators of the Pathology Working Group (PWG). The QA report and the reviewed slides were submitted to the Division of Translational Toxicology (DTT) pathologist, who reviewed and addressed any inconsistencies in the diagnoses made by the study laboratory and QA pathologists. The QA/PWG pathologist presented representative histopathology slides containing examples of lesions related to test agent administration, examples of disagreements in diagnoses between the laboratory and QA pathologist, or lesions of general interest to the PWG for review. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, QA pathologist, and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^38^ and Boorman et al.^39^

## Statistical Methods

Statistical methods were chosen based on distributional assumptions as well as on the need to incorporate within-litter correlation among animals (for the perinatal rat studies). Unless specifically mentioned, all endpoints were tested for a trend across exposure groups, followed by pairwise tests for each exposed group against the control group. Significance of all trend and pairwise tests is reported at both 0.05 and 0.01 levels.

### Calculation and Analysis of Gross and Nonneoplastic Lesion Incidences

For mice and rats, incidences of gross findings and histopathology were summarized as number of animals affected. Fisher’s exact test,^41^ a procedure that uses the overall proportion of affected animals, was used to determine statistical significance between exposed and vehicle control animals, and the Cochran-Armitage trend test was used to test for significant trends.^42^

### Analysis of Continuous Variables

Before statistical analysis, outliers identified using the Dixon and Massey test^43^ for small samples (n < 20) and Tukey’s outer fences method^44^ for large samples (n ≥ 20) were examined by DTT personnel, and biologically implausible values (likely due to experimental error) were eliminated from the analysis.

In most instances, no considerations for litter effects were necessary in the analysis of the continuous data. This was the case for all of the mice data, for the F_0_ rat data, and for F_1_ rat data in which the cohort consisted of only one animal per litter. In these instances, organ and body weight measurements, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^45^ and Williams.^46,47^

When litter effects were present, body weight endpoints were analyzed using linear mixed models, with litters as a random effect. To adjust for multiple comparisons, a Dunnett-Hsu adjustment was used.^48^ Pup weights were adjusted for litter size, as described below.

Water consumption, clinical chemistry, hematology, urinalysis, tissue concentration, litter sizes, gestational length, pup survival, spermatid, and epididymal spermatozoal measurements typically have skewed distributions. When litter effects were not present, these endpoints were analyzed using the nonparametric multiple comparison methods of Shirley^49^ (as modified by Williams^50^) and Dunn.^51^ For all continuous variables without litter effects, the Jonckheere test^52^ was used to assess the significance of the exposure concentration-related trends and to determine, at the 0.01 level of significance, whether a trend-sensitive test (the Williams or Shirley test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic exposure concentration-related trend (the Dunnett or Dunn test).

When litter effects were present for non-normally distributed continuous endpoints (e.g., hematology data for F_1_ interim rats), the trend across exposure groups was analyzed by a permutation test based on the Jonckheere trend test, implemented by randomly permuting whole litters across exposure groups and bootstrapping within the litters (see, for example, Davison and Hinckley^53^). Pairwise comparisons were made using a modified Wilcoxon test that incorporated litter effects.^54^ The Hommel procedure was used to adjust for multiple comparisons.^55^

For the sodium metavanadate F_1_ core study rats, only the 500 mg/L group contained multiple animals per sex per litter. Because all other groups in the study contained only one animal per litter, litter-based methods were not used in the analysis of these animals.

### Analysis of Gestational and Fertility Indices

Cochran-Armitage trend tests were used to test the significance of trends in gestational and fertility indices across exposure groups. Fisher’s exact test was used to conduct pairwise comparisons of each exposed group with the control group. P values for these analyses are two-sided.

### Body Weight Adjustments

Because body weights typically decrease with increasing litter size, adjusting body weight for litter size in the analysis of fetal and pup weights can provide additional precision to detect test article effects.^56^ Body weight adjustments are appropriate when the litter effect, as evidenced by decreasing weights with increasing litter size, is relatively constant across exposure concentrations. Preweaning pup body weights were adjusted for live litter size by fitting a linear model to body weights as a function of exposure concentration and litter size, with the coefficient of litter size retained for adjustment as above. Prestandardization PND 4 body weights were adjusted for PND 1 litter size, and body weights measured between PND 4 poststandardization and PND 21 were adjusted for PND 4 poststandardization litter size. After adjustment, body weights were analyzed with a linear mixed model with a random litter effect.

### Analysis of Time-to-event Data

Time-to-event endpoints, such as day of attainment of BPS and VO, have several features that require careful model selection: non-normality of distributions, litter-based correlation, and censored values when attainment was not observed before the end of the observation period. Further, growth retardation, reflected in the weaning weight, is an important covariate in the case of BPS and VO given the relationship between normal day of expected attainment and body weight.

When attainment times were approximately normally distributed and attainment was observed for all or most animals, two approaches for modeling discrete developmental endpoints were taken. First, a mixed model was fit to attainment day as a function of exposure concentration with a random litter effect. For BPS and VO, a second mixed model was fit to attainment day as a function of exposure concentration and weaning weight with a random litter effect. Dunnett-Hsu adjustments were used to account for multiple comparisons.^48^

To calculate mean attainment values adjusted for weaning weight, a linear model was fit to attainment day as a function of exposure concentration and weaning weight. The estimated coefficient of weaning weight was then used to adjust each attainment day based on the difference between the measured weaning weight and the mean weaning weight.

### Analysis of Vaginal Cytology Data

Vaginal cytology data consist of daily observations of estrous cycle stages over a 16-day period. Differences from the control group for cycle length and the number of cycles were analyzed using the Shirley and Dunn tests, as described above.

To identify disruptions in estrous cyclicity, a continuous-time Markov chain model (multistate model) was fit using a maximum likelihood approach,^57^ producing estimates of stage lengths for each exposure group. Confidence intervals for these estimates were obtained from bootstrap sampling of the individual animal cycle sequences. Stage lengths that were significantly different from the control animals were identified using permutation testing.

## Quality Assurance Methods

The 3-month studies were conducted in compliance with U.S. Food and Drug Administration Good Laboratory Practice Regulations.^58^ In addition, the 3-month study reports were audited retrospectively by an independent QA contractor against study records submitted to the NTP Archives. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Toxicity Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by DTT staff, and all comments were resolved or otherwise addressed during the preparation of this toxicity report.

## Genetic Toxicology

The genetic toxicity of sodium metavanadate and vanadyl sulfate was assessed by testing whether the chemicals induced mutations in various strains of Salmonella typhimurium and Escherichia coli and increased the frequency of micronucleated erythrocytes in rat and mouse peripheral blood. The protocol for these studies and the results are given in Appendix D.

The genetic toxicity studies have evolved from an earlier effort to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the relationship between the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were developed originally to clarify proposed mechanisms of chemical-induced DNA damage given the relationship between electrophilicity and mutagenicity^59^ and the somatic mutation theory of cancer.^60,61^ Not all cancers, however, arise through genotoxic mechanisms.

### Bacterial Mutagenicity

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites.^62^ A positive response in the Salmonella test was shown to be the most predictive in vitro indicator for rodent carcinogenicity (89% of the Salmonella mutagens are rodent carcinogens).^63,64^ Additionally, no battery of tests that included the Salmonella test improved predictivity over the Salmonella test alone. Other tests, however, can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation.

### Peripheral Blood Micronucleus Test

Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division.^65,66^ Acute in vivo bone marrow chromosome aberration and micronucleus tests appear to be less predictive of carcinogenicity than the Salmonella test.^67,68^ However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies.^69^ Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, determination of in vivo genetic effects is important to overall understanding of risks associated with exposure to a particular chemical.