# Introduction

## Chemical and Physical Properties

Vanadyl sulfate and sodium metavanadate are inorganic vanadium compounds with +4 (tetravalent, V^4+^) and +5 (pentavalent, V^5+^) oxidation states, respectively (Table 1). Vanadyl sulfate is a blue crystalline solid with a melting point of 265°C and is highly soluble in water (467 g/L at 20°C).^4^ Sodium metavanadate is colorless to yellow in crystalline form or a cream-colored solid with a melting point of 630°C and a water solubility of 211 g/L at 25°C.^5-7^

Table 1 Vanadium Compounds Evaluated

Chemical Name | Chemical Formula | Oxidation State | CASRN | Molecular Weight (g/mol) | Structure
Vanadyl Sulfate^a^ | VOSO_4_ | V^4+^ | 27774-13-6 | 163.01
Sodium Metavanadate^b^ | NaVO_3_ | V^5+^ | 13718-26-8 | 121.93

^a^ Synonyms: vanadium, oxo(sulfato(2-)-O)-; vanadium oxide sulphate; vanadic sulfate; oxovanadium(2+) sulfate; oxovanadium(IV) sulfate; vanadium(IV) oxysulfate; (oxido)vanadium(2+) sulfate; oxosulfatovanadium(IV); oxovanadium(IV) sulfate; vanadium oxide sulfate; vanadium oxosulfate; vanadium oxysulfate; vanadium sulfate; vanadyl monosulfate; vanadin(IV) oxide sulfate.

^b^ Synonyms: sodium (meta)vanadate; sodium vanadate(V); vanadic acid, monosodium salt; sodium trioxovanadate; sodium vanadium oxide; monosodium trioxovanadate(1-); sodium vanadate; sodium trioxidovanadate(1-); sodium vanadium trioxide; vanadic acid (HVO_3_), sodium salt (8Cl).

## Production, Use, and Human Exposure

Vanadium is a naturally occurring element found in the earth’s crust (approximately 100 ppm) and in a variety of mineral substances.^8^ According to a study conducted in the 1980s, human exposure from background levels of vanadium in dietary sources is estimated at 6–18 μg/day (based on age group and sex) in the United States; young male populations are estimated to have the highest daily intake of 18.3 µg/day.^9^ The primary forms of vanadium identified in food have been characterized and reported as vanadyl (V^4+^) and vanadate (V^5+^), likely because they are the more stable forms.^10^ The contribution to background levels of vanadium in food is largely attributed to natural occurrences of the element, including weathering rock, soil erosion, and continental dust.

Vanadium also occurs naturally in coal and petroleum crude oils, which can lead to anthropogenic contributions to oral human exposure. The average concentration of vanadium in coal in the United States is approximately 30 ppm, with a range (15–34 ppm) determined by geographic origin.^8^ By comparison, concentrations of vanadium in residual oil have a much larger range (1–1,400 ppm).^8^ Residual oil is primarily used in oil-fired power plants and industrial boilers. Fly ash, a combustion product of coal and residual oil, contains vanadium and is a potential source of anthropogenic contamination of drinking water sources.^8^

In addition to natural and anthropogenic sources of vanadium that may lead to oral exposure in humans, the V^4+^ (including vanadyl sulfate) and V^5+^ (including sodium metavanadate) forms of vanadium are also sold in dietary supplements.^11^ These supplements have purported benefits of improving glucose metabolism in diabetic patients, reducing hypertension and hyperlipidemia, and treating osteoporosis. Some of these uses are supported by mechanistic information for V^4+^ that indicate it is a protein tyrosine phosphatase inhibitor.^12^

## Toxicity Assessments and Regulatory Status

In 2012, the Agency for Toxic Substances and Disease Registry (ATSDR) published a thorough review of the existing literature for health effects resulting from oral vanadium exposure (and other routes) in humans and experimental animals.^8^ In studies of rats and mice orally exposed to sodium metavanadate or vanadyl sulfate, some findings were consistent across multiple studies. Hematological effects—including reduced hemoglobin, hematocrit, or erythrocytes and increased reticulocytes—were observed in two studies in Wistar rats exposed to sodium metavanadate.^13,14^

Several studies in Wistar rats, Sprague Dawley rats, or Swiss mice exposed orally to either sodium metavanadate or vanadyl sulfate reported developmental and reproductive effects. Developmental effects included reduced pup body weight and survival,^15-17^ and reproductive effects included reduced fertility and sperm counts.^18-20^

Increased blood pressure was observed in three studies of oral sodium metavanadate exposure in male Sprague Dawley rats.^19^ Other cardiac effects included increased heart rate in male Sprague Dawley rats orally exposed to sodium metavanadate and reduced aorta diameter in male Swiss albino rats dosed via intraperitoneal injection with vanadyl sulfate.^21^ Impaired neurobehavioral performance was observed in two studies of male Sprague Dawley rats orally dosed with sodium metavanadate.^22,23^

Subsequent to this review, the results of 14-day drinking water studies of sodium metavanadate and vanadyl sulfate in adult rats and mice were published.^2,3^ The studies described in Roberts et al.^2^ were conducted as part of the NTP vanadium research program and were important for the study design and concentration selection for the studies described here.

Elemental vanadium is included in the Contaminant Candidate List (CCL) of substances that do not have national regulatory guidelines and are known or anticipated to occur in public water systems.^24^ Vanadium has been included on the CCL since its inception in 1998 with CCL1.^25^ In 2020, the Environmental Protection Agency Integrated Risk Information System program initiated an assessment of vanadium and vanadium compounds following oral exposure.^26^

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

Interconversion between oxidation states and complex speciation under the conditions in the gastrointestinal (GI) tract and during transport in the systemic circulation makes investigating the absorption, distribution, metabolism, and excretion (ADME) behavior of vanadyl (V^4+^) and vanadate (V^5+^) compounds difficult. Higher absorption of vanadate compared to vanadyl has been reported due to differential speciation in the GI tract. For example, intestinal absorption of the oxo-anions (e.g., H_2_VO^4-^, HVO_4_^2-^) of vanadate is known to be higher than that of the oxo-cations (e.g.,VO^2+^) of vanadyl compounds.^27^

Limited ADME data available on vanadyl and vanadate compounds point to low absorption of vanadium following oral exposure in rodents; the absorbed dose is distributed into tissues with low retention and excreted via urine.^8,27-30^ Because speciation of vanadium using available analytical techniques is challenging, especially in biological matrices, data available are based on measurement of total vanadium. Following exposure of female Wistar rats to 100 ppm of sodium metavanadate in feed for 7 days, the majority of the dose was excreted in feces (83.5%), with small amounts recovered in urine (0.86%).^28^ Vanadium was distributed to tissues, with higher concentrations found in bone, spleen, kidney, and liver relative to other tissues. Bogden et al.^29^ reported similar findings following exposure of up to 25 ppm vanadium as sodium metavanadate via feed in female Sprague Dawley rats for 2 weeks; significantly higher levels were measured in plasma compared to erythrocytes.^29^ In male Wistar rats, following exposure of 5 or 50 ppm vanadyl sulfate or sodium orthovanadate in drinking water for up to 3 months, vanadium concentrations increased in the kidney, liver, bone, muscle tissue, digestive tract, and blood over time and with increasing exposure concentrations.^30^ Higher concentrations of vanadium were observed in tissues following exposure to sodium orthovanadate compared to vanadyl sulfate. The concentration of vanadium in all tissues except the bone declined rapidly after cessation of exposure, although sodium orthovanadate-exposed animals exhibited relatively high concentrations of vanadium, especially in the bone and kidney, 6 weeks following cessation of exposure.

In Sprague Dawley rats, the elimination half-life of vanadium in tissues following exposure to 160 μmol vanadium/kg body weight/day as vanadyl sulfate or sodium orthovanadate via a liquid diet for 1 week ranged from 3.18 to 15.95 days, with the kidney and liver having the shortest half-life (<4 days) and the testes having the longest (13.50–15.95 days).^31^ In general, half-lives were slightly longer following administration of sodium orthovanadate compared to vanadyl sulfate. Ramanadham et al.^32^ reported an elimination half-life of 11.7 days in the kidney following exposure to 0.75 mg/mL vanadyl sulfate trihydrate via drinking water in Wistar rats for 3 weeks.^32^ Following a single gavage dose of 37.5 or 75 mg/kg vanadyl sulfate pentahydrate (7.56 or 15.12 mg vanadium/kg, respectively) in male Wistar rats, the estimated blood elimination half-life was approximately 173 hours (7.2 days); absolute bioavailability was approximately 16%.^33^ Fetal transfer of vanadium has been reported following exposure of pregnant mice to vanadyl sulfate pentahydrate at doses ≤150 mg/kg/day from gestation day (GD) 6 through GD 15.^34^

### Humans

Limited ADME data in the literature for vanadyl compounds suggest poor absorption of vanadium following oral exposure.^8,27,35,36^ Following ingestion of 50–125 mg ammonium vanadyl tartrate per day, <1% of the dose was excreted in urine within 24 hours.^35^ Following daily oral dosing of diabetic patients with 25, 50, or 100 mg vanadium as vanadyl sulfate for 6 weeks, serum and blood vanadium concentrations were dose-proportional, and blood and serum elimination half-lives were between 4.6 and 5.6 days.^36^

## Study Rationale

Vanadium was selected for evaluation via drinking water due to potential widespread oral human exposure and identified data collection needs,^8^ which include comprehensive toxicological characterization and evaluation of test articles with different oxidation states under similar experimental designs and test settings. To address these information gaps, vanadyl sulfate and sodium metavanadate were selected as representative test articles for the tetravalent (V^4+^) and pentavalent (V^5+^) forms, respectively. Three-month drinking water studies were conducted with both test articles in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats (including a perinatal phase) and B6C3F1/N mice.