# Appendix E Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NTP-DATA-TOX-106.

## E.1 Perinatal and Three-month Sodium Metavanadate Study – Rats

### E.1.1 Data Tables

I01 – Animal Removal Summary

I02 – Animal Removals

I03 – Growth Curve

I03C – Growth Curve

I04 – Mean Body Weight Summary

I04G – Mean Body Weight Gain

I05 – Clinical Observations Summary

I05P – Pup Clinical Observations Summary

I07 – Mean Water Consumption

I08 – Mean Test Compound Consumption

PA02R – Neoplastic Lesion Summary with Percent and Litter Incidence

PA03R – Non-Neoplastic Summary with Percent and Litter Incidence

PA05R – Incidence Rates of Neoplastic Lesions with Litter Incidence

PA06 – Organ Weight Summary

PA10R – Statistical Analysis of Nonneoplastic Lesions with Litter Incidence

PA14 – Individual Animal Pathology Data

PA18R – Non-Neoplastic Lesion Summary with Mean Severity Grade and Litter Incidence

PA41 – Clinical Chemistry Summary

PA43 – Hematology Summary

PA44 – Urinalysis Data Summary

PA46 – Summary of Gross Pathology

PA48 – Summary of Tissue Concentration

R01 – Multigeneration Cross-Reference

R02 – Reproductive Performance Summary

R03 – Summary of Litter Data

R06 – Andrology Summary

R16 – Pubertal Markers Summary

R19 – Pup Mean Body Weight Summary

R19C – Pup Growth Curve

R19G – Pup Mean Body Weight Gain

Vaginal Cytology Markov Model

Vaginal Cytology Plots

Vaginal Cytology Summary

### E.1.2 Individual Animal Data

Individual Animal Andrology Data

Individual Animal Body Weight Data

Individual Animal Clinical Chemistry Data

Individual Animal Clinical Observations Data

Individual Animal Consumption Data

Individual Animal Developmental Markers Data

Individual Animal Gross Pathology Data

Individual Animal Hematology Data

Individual Animal Histopathology Data

Individual Animal Litter Data

Individual Animal Organ Weight Data

Individual Animal Pup Body Weight Data

Individual Pup Clinical Observations Data

Individual Animal Removal Reasons Data

Individual Animal Reproductive Performance Data

Individual Animal Tissue Concentration Data

Individual Animal Urinalysis Data

Individual Animal Whole Litter Weight Data

## E.2 Three-month Sodium Metavanadate Study – Mice

### E.2.1 Data Tables

I01 – Animal Removal Summary

I02 – Animal Removals

I03 – Growth Curve

I03C – Growth Curve

I04 – Mean Body Weight Summary

I04G – Mean Body Weight Gain

I05 – Clinical Observations Summary

I07 – Mean Water Consumption

I08 – Mean Test Compound Consumption

PA02 – Neoplastic Lesion Summary with Percent Incidence

PA03 – Non-neoplastic Lesion Summary with Percent Incidence

PA05 – Incidence Rates of Neoplastic Lesions with Systemic Lesions Abridged

PA06 – Organ Weights Summary

PA08 – Statistical Analysis of Neoplastic Lesions

PA10 – Statistical Analysis of Nonneoplastic Lesions

PA14 – Individual Animal Pathology Data

PA18 – Incidence Rates of Non-neoplastic Lesions by Anatomic Site with Average Severity Grade

PA43 – Hematology Summary

PA46 – Summary of Gross Pathology

R06 – Andrology Summary

Vaginal Cytology Markov Model

Vaginal Cytology Plots

Vaginal Cytology Summary

### E.2.2 Individual Animal Data

Individual Animal Andrology Data

Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Consumption Data

Individual Animal Gross Pathology Data

Individual Animal Hematology Data

Individual Animal Histopathology Data

Individual Animal Organ Weight Data

Individual Animal Removal Reasons Data

## E.3 Perinatal and Three-month Vanadyl Sulfate Study – Rats

### E.3.1 Data Tables

I01 – Animal Removal Summary

I02 – Animal Removals

I03 – Growth Curve

I03C – Growth Curve

I04 – Mean Body Weight Summary

I04G – Mean Body Weight Gain

I05 – Clinical Observations Summary

I05P – Pup Clinical Observations Summary

I07 – Mean Water Consumption

I08 – Mean Test Compound Consumption

PA02R – Neoplastic Lesion Summary with Percent and Litter Incidence

PA03R – Non-neoplastic Lesion Summary with Percent and Litter Incidence

PA05R – Incidence Rates of Neoplastic Lesions with Litter Incidence Systemic Lesions Abridged

PA06 – Organ Weight Summary

PA08R – Statistical Analysis of Neoplastic Lesions with Litter Incidence

PA10R – Statistical Analysis of Nonneoplastic Lesions with Litter Incidence

PA14 – Individual Animal Pathology Data

PA18R – Non-neoplastic Lesion Summary with Mean Severity Grade and Litter Incidence

PA41 – Clinical Chemistry Summary

PA43 – Hematology Summary

PA44 – Urinalysis Data Summary

PA46 – Summary of Gross Pathology

PA48 – Summary of Tissue Concentration

R01 – Multigeneration Cross-Reference

R02 – Reproductive Performance Summary

R03 – Summary of Litter Data

R06 – Andrology Summary

R16 – Pubertal Markers Summary

R19 – Pup Mean Body Weight Summary

R19C – Pup Growth Curve

R19G – Pup Mean Body Weight Gain

Vaginal Cytology Markov Model

Vaginal Cytology Plots

Vaginal Cytology Summary

### E.3.2 Individual Animal Data

Individual Animal Andrology Data

Individual Animal Body Weight Data

Individual Animal Clinical Chemistry Data

Individual Animal Clinical Observations Data

Individual Animal Consumption Data

Individual Animal Developmental Markers Data

Individual Animal Gross Pathology Data

Individual Animal Hematology Data

Individual Animal Histopathology Data

Individual Animal Litter Data

Individual Animal Organ Weight Data

Individual Animal Pup Body Weight Data

Individual Animal Pup Clinical Observations Data

Individual Animal Removal Reasons Data

Individual Animal Reproductive Performance Data

Individual Animal Tissue Concentration Data

Individual Animal Urinalysis Data

Individual Whole Litter Weight Data

## E.4 Three-month Vanadyl Sulfate Study – Mice

### E.4.1 Data Tables

I01 – Animal Removal Summary

I02 – Animal Removals

I03 – Growth Curve

I03C – Growth Curve

I04 – Mean Body Weight Summary

I04G – Mean Body Weight Gain

I05 – Clinical Observations Summary

I07 – Mean Water Consumption

I08 – Mean Test Compound Consumption

PA02 – Neoplastic Lesion Summary with Percent Incidence

PA03 – Non-Neoplastic Lesion Summary with Percent Incidence

PA05 – Incidence Rates of Neoplastic Lesions with Systemic Lesions Abridged

PA06 – Organ Weights Summary

PA08 – Statistical Analysis of Neoplastic Lesions

PA10 – Statistical Analysis of Nonneoplastic Lesions

PA14 – Individual Animal Pathology Data

PA18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grade

PA43 – Hematology Summary

PA46 – Summary of Gross Pathology

R06 – Andrology Summary

Vaginal Cytology Markov Model

Vaginal Cytology Plots

Vaginal Cytology Summary

### E.4.2 Individual Animal Data

Individual Animal Andrology Data

Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal Consumption Data

Individual Animal Gross Pathology Data

Individual Animal Hematology Data

Individual Animal Histopathology Data

Individual Animal Organ Weight Data

Individual Animal Removal Reasons Data

## E.5 Genetic Toxicology

### E.5.1 Sodium Metavanadate (13718-26-8) in Micronucleus Study in Sprague Dawley Rats

G04 – In Vivo Micronucleus Summary

Individual Animal In Vivo Micronucleus Data

### E.5.2 Sodium Metavanadate (13718-26-8) in Micronucleus Study in B6C3F1/N Mice

G04 – In Vivo Micronucleus Summary

Individual Animal In Vivo Micronucleus Data

### E.5.3 Sodium Metavanadate (13718-26-8) in Salmonella/E.coli Mutagenicity Test or Ames Test

G06 – Ames Summary Data

### E.5.4 Vanadyl Sulfate (27774-13-6) in Micronucleus Study in Sprague Dawley Rats

G04 – In Vivo Micronucleus Summary

Individual Animal In Vivo Micronucleus Data

### E.5.5 Vanadyl Sulfate (27774-13-6) in Micronucleus Study in B6C3F1/N Mice

G04 – In Vivo Micronucleus Summary

Individual Animal In Vivo Micronucleus Data

### E.5.6 Vanadyl Sulfate (27774-13-6) in Salmonella/E.coli Mutagenicity Test or Ames Test

G06 – Ames Summary Data