# Appendix D Genetic Toxicology

## D.1 Evaluation Protocol

The National Toxicology Program (NTP) considers biological as well as statistical factors to determine an overall assay result. For an individual assay, the statistical procedures for data analysis are described in the following protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. In such cases, all the data are critically evaluated with attention given to possible protocol variations in determining the weight of evidence for an overall conclusion of chemical activity in an assay. For in vitro assays conducted with and without exogenous metabolic activation, results obtained in the absence of activation are analyzed separately from results obtained in the presence of activation. The summary table in the abstract of this toxicity report presents the Division of Translational Toxicology’s (DTT’s) scientific judgment regarding the overall evidence for activity of the chemical in an assay.

## D.2 Bacterial Mutagenicity

### D.2.1 Bacterial Mutagenicity Test Protocol

Testing procedures were modified from those originally reported by Zeiger et al.^94^ Coded samples of sodium metavanadate and vanadyl sulfate (the same chemical lots that were used in the perinatal and 3-month bioassays) were incubated with the Salmonella typhimurium (TA98, TA100) or Escherichia coli WP2 uvrA (pKM101) tester strains either in buffer or S9 mix (metabolic activation enzymes and cofactors from phenobarbital/benzoflavone-induced male Sprague Dawley rat liver) for 20 minutes at 37°C. Top agar supplemented with L-histidine (or tryptophan for the E. coli strain) and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine- or tryptophan-independent mutant colonies arising on these plates were counted after incubation for 2 days at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and at least six doses of sodium metavanadate or vanadyl sulfate. The highest concentration of sodium metavanadate and vanadyl sulfate tested was limited by toxicity in strains TA98 and TA100; E. coli was tested up to the assay limit dose of 6,000 μg/plate. All trials were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine- or tryptophan-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose-related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed after chemical treatment. No minimum percentage or fold increase is required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

### D.2.2 Results

Neither sodium metavanadate nor vanadyl sulfate was mutagenic in Salmonella typhimurium strains TA98 and TA100 or in Escherichia coli strain WP2 uvrA (pKM101) in tests conducted with and without exogenous metabolic activation provided by phenobarbital/benzoflavone-induced male rat liver S9 and cofactors (Table D-1, Table D-2). Sodium metavanadate was tested at concentrations of 0.5–100 µg/plate in TA98 with or without S9 mix and in TA100 at concentrations of 0.5–100 µg/plate without S9 mix and 1.0–500 µg/plate with S9 mix. For TA98 and TA100, the top concentration was limited by cytotoxicity. In E. coli, sodium metavanadate was tested at concentrations of 40–6,000 µg/plate with or without S9 mix. Vanadyl sulfate was tested at concentrations of 0.4–100 µg/plate in TA98 and TA100 with or without S9 mix. For TA98, the top concentration was limited by cytotoxicity. In E. coli, vanadyl sulfate was tested at concentrations of 4.0–6,000 µg/plate with or without S9 mix.

Table D-1 Mutagenicity of Sodium Metavanadate in Bacterial Tester Strains^a^

Strain | Concentration (μg/plate) | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9
TA98
| 0 | 19 ± 1.0 | 21 ± 1.5 | 24 ± 7.6 | 34 ± 1.7
| 0.5 | 21 ± 3.8 | 21 ± 1.7 | 30 ± 0.7 | 27 ± 3.2
| 1.0 | 18 ± 3.0 | 22 ± 2.6 | 23 ± 3.0 | 26 ± 1.2
| 2.5 | 18 ± 2.5 | 22 ± 1.2 | 24 ± 6.4 | 24 ± 1.2
| 10.0 | 12 ± 2.5 | 18 ± 3.8 | 29 ± 3.2 | 27 ± 2.3
| 20.0 | – | Toxic | – | –
| 40.0 | Toxic | Toxic | 15 ± 2.8 | 9 ± 1.5
| 100.0 | Toxic | – | Toxic | Toxic
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control^b^ | | 547 ± 39.3 | 377 ± 13.5 | 1,330 ± 58.9 | 1,477 ± 35.6
TA100
| 0 | 105 ± 5.4 | 108 ± 1.5 | 95 ± 4.7 | 113 ± 2.6
| 0.5 | 98 ± 9.7 | 120 ± 3 | – | –
| 1.0 | 108 ± 8.2 | 111 ± 3.2 | – | 105 ± 9.6
| 2.5 | 101 ± 9.2 | 120 ± 1.5 | 97 ± 8.9 | 120 ± 4.3
| 10.0 | 125 ± 4.9 | 117 ± 1.5 | 90 ± 2 | 98 ± 18.8
| 20.0 | – | 113 ± 6.5 | – | –
| 40.0 | 22 ± 8.1 | 33 ± 8.5 | 99 ± 8.7 | 97 ± 6.6
| 100.0 | 8 ± 2 | – | 109 ± 3.2 | 97 ± 13.5
| 200.0 | – | – | Toxic | Toxic
| 500.0 | – | – | Toxic | –
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control | | 772 ± 18.2 | 887 ± 32.3 | 1,594 ± 195.9 | 2,165 ± 73.1
Escherichia coli WP2 uvrA (pKM101)
| 0 | 150 ± 7.0 | 161 ± 5.5 | 181 ± 11.1 | 150 ± 7
| 40.0 | – | 143 ± 2.3 | – | 166 ± 9.8
| 100.0 | 141 ± 9.1 | 149 ± 0 | 152 ± 3.4 | 146 ± 7.2
| 200.0 | 153 ± 14.9 | 133 ± 4 | 169 ± 2.9 | 146 ± 8.5
| 500.0 | 131 ± 3.5 | 121 ± 10.8 | 156 ± 3.8 | 149 ± 6.2
| 1,000.0 | 130 ± 11.5 | – | 151 ± 18.1 | –
| 2,000.0 | – | 116 ± 11.4 | – | 133 ± 18.4
| 3,000.0 | 112 ± 4.9 | – | 138 ± 12.2 | –
| 6,000.0 | 120 ± 5.5 | 133 ± 3.8 | 140 ± 6.4 | 140 ± 2.1
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control | | 2,697 ± 29.4 | 612 ± 59.6 | 1,088 ± 18.5 | 1,051 ± 66.2

^a^ Studies performed at Integrated Laboratory Systems, LLC. Data are presented as revertants/plate (mean ± standard error) from three plates; 0 μg/plate served as the solvent control (distilled water).

^b^ The positive controls in the absence of metabolic activation were 2-nitrofluorene (TA98), sodium azide (TA100), and methyl methane sulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table D-2 Mutagenicity of Vanadyl Sulfate in Bacterial Tester Strains^a^

Strain | Concentration (μg/plate) | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9
TA98
| 0 | 26 ± 4.6 | 18 ± 1.7 | 28 ± 4.0 | 27 ± 3.0
| 0.4 | 21 ± 1.8 | 20 ± 2.3 | 30 ± 1.8 | 24 ± 3.3
| 1.0 | 24 ± 1.5 | 21 ± 3.3 | 24 ± 1.9 | 30 ± 2.2
| 4.0 | 24 ± 2.6 | 18 ± 4.3 | 28 ± 2.9 | 25 ± 3.0
| 10.0 | 16 ± 3.1 | 19 ± 1.5 | 24 ± 3.2 | 30 ± 2.0
| 40.0 | 9 ± 2.5 | 6 ± 3.2 | 27 ± 4.3 | 32 ± 3.2
| 100.0 | 5 ± 1.9 | Toxic | 14 ± 2.2 | 12 ± 1.5
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control^b^ | | 591 ± 17.3 | 608 ± 103.6 | 1,576 ± 34.5 | 1,872 ± 57.8
TA100
| 0 | 103 ± 7.1 | 113 ± 4.9 | 98 ± 5.7 | 104 ± 9.3
| 0.4 | 102 ± 8.8 | 98 ± 10.9 | 105 ± 2.6 | 113 ± 3.4
| 1.0 | 115 ± 16.8 | 101 ± 5.0 | 92 ± 1.5 | 99 ± 9.6
| 4.0 | 88 ± 7.6 | 100 ± 4.4 | 92 ± 5.5 | 111 ± 5.4
| 10.0 | 103 ± 5.0 | 114 ± 4.4 | 99 ± 5.7 | 125 ± 5.5
| 40.0 | 100 ± 10.4 | 145 ± 6.7 | 88 ± 10.1 | 89 ± 2.0
| 100.0 | 30 ± 5.2 | 59 ± 4.1 | 83 ± 3.5 | 101 ± 4.8
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control | | 693 ± 19.6 | 699 ± 75.0 | 3,780 ± 78.9 | 2,306 ± 28.6
Escherichia coli WP2 uvrA (pKM101)
| 0 | 159 ± 6.3 | 159 ± 11.6 | 177 ± 2.1 | 178 ± 9.0
| 4.0 | 122 ± 9.5 | – | 169 ± 10.5 | –
| 10.0 | 141 ± 7.2 | – | 170 ± 9.0 | –
| 40.0 | 163 ± 8.4 | 145 ± 5.3 | 148 ± 10.1 | 179 ± 11.6
| 100.0 | 134 ± 6.7 | 134 ± 5.2 | 149 ± 7.7 | 175 ± 6.8
| 400.0 | 132 ± 8.2 | 141 ± 7.8 | 161 ± 8.7 | 149 ± 12.5
| 1,000.0 | 151 ± 4.1 | 143 ± 14.7 | 155 ± 4.1 | 157 ± 4.4
| 3,000.0 | – | 139 ± 10.1 | – | 166 ± 6.6
| 6,000.0 | – | 148 ± 3.5 | – | 198 ± 5.5^c^
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control | | 2,192 ± 96.1 | 1,047 ± 78.2 | 1,310 ± 26.8 | 1,070 ± 30.1

^a^ Studies performed at Integrated Laboratory Systems, LLC. Data are presented as revertants/plate (mean ± standard error) from three plates; 0 μg/plate served as the solvent control (distilled water).

^b^ The positive controls in the absence of metabolic activation were 2-nitrofluorene (TA98), sodium azide (TA100), and methyl methane sulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

^c^ Precipitate on plate.

## D.3 Micronucleus Assay

### D.3.1 Peripheral Blood Micronucleus Test Protocol

At termination of the 3-month toxicity studies of sodium metavanadate and vanadyl sulfate, blood samples (approximately 200 μL) were collected from male and female rats and mice, placed in ethylenediaminetetraacetic acid (EDTA)-coated tubes, and shipped overnight to the testing laboratory. Upon arrival, blood samples were fixed in ultracold methanol using a MicroFlowPLUS Kit (Litron Laboratories, Rochester, NY) according to the manufacturer’s instructions. Fixed samples were stored in a −80°C freezer until analysis. Thawed blood samples were analyzed for frequency of micronucleated immature erythrocytes (i.e., reticulocytes or polychromatic erythrocytes [PCEs]) and mature erythrocytes (i.e., normochromatic erythrocytes [NCEs]) using a flow cytometer^95^; both the mature and immature erythrocyte populations can be analyzed separately by employing special cell surface markers to differentiate the two cell types. Because the very young reticulocyte subpopulation (CD71+ cells) can be targeted using this technique, rat blood samples can be analyzed for damage that occurred in the bone marrow within the past 24–48 hours, before the rat spleen appreciably alters the percentage of PCEs in circulation.^96^ In mice, both the mature and immature erythrocyte populations can be evaluated for micronucleus frequency because the mouse spleen does not sequester and eliminate damaged erythrocytes. Damaged erythrocytes achieve steady state in the peripheral blood of mice after 4 weeks of continuous exposure. Approximately 20,000 PCEs and 1 × 10^6^ NCEs were analyzed per animal for frequency of micronucleated cells, and the percentage of immature erythrocytes (% PCE) was calculated as a measure of bone marrow toxicity resulting from chemical exposure.

Prior experience with the large number of cells scored using flow cytometric scoring techniques^97^ suggests it is reasonable to assume that the proportion of micronucleated reticulocytes is approximately normally distributed. The statistical tests selected for trend and for pairwise comparisons with the control group depend on whether the variances among the groups are equal. The Levene test at α = 0.05 is used to test for equal variances. In the case of equal variances, linear regression is used to test for a linear trend with exposure concentration, and the Williams test is used to test for pairwise differences between each exposed group and the control group. In the case of unequal variances, the Jonckheere test is used to test for linear trend, and the Dunn test is used for pairwise comparisons of each exposed group with the control group. To correct for multiple pairwise comparisons, the p value for each comparison with the control group is multiplied by the number of comparisons made. In the event that this product is >1.00, it is replaced with 1.00. Trend tests and pairwise comparisons with the control group are considered statistically significant at p ≤ 0.025.

In the micronucleus test, it is preferable to base a positive result on the presence of both a positive trend as well as at least one significantly elevated exposed group compared with the corresponding control group. In addition, historical control data are used to evaluate the biological significance of any observed response. Both statistical significance and biological significance are considered when arriving at a call. The presence of either a positive trend or a single significant exposed group generally results in an equivocal call. The absence of both a trend and any significant differences between exposed groups and the control group results in a negative call. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed (in acute studies), and the magnitudes of those effects.

### D.3.2 Results

At the end of the 3-month studies of sodium metavanadate and vanadyl sulfate, peripheral blood samples were obtained from male and female rats and mice and analyzed for the frequency of micronucleated immature erythrocytes (i.e., reticulocytes or polychromatic erythrocytes [PCEs]) and mature erythrocytes (i.e., normochromatic erythrocytes [NCEs]). In male and female rats, the reticulocyte population is the only red blood cell population that can be accurately assessed for micronucleus frequency in peripheral blood of rats due to efficient splenic scavenging of damaged erythrocytes.

In the sodium metavanadate study, a significant trend test was observed for the frequency of micronucleated reticulocytes in male rats, meeting statistical criteria for an equivocal result (Table D-3). However, the frequencies of micronucleated reticulocytes for the control group and all groups exposed to sodium metavanadate were well within the laboratory historical vehicle control (mean ± 2 standard deviations, or 95% confidence interval); therefore, this result was judged to be negative. Significant increases in the percentage of reticulocytes were observed in male rats, indicating that exposure to sodium metavanadate had a stimulatory effect on erythropoiesis. No increases in the frequencies of micronucleated reticulocytes were observed in female rats after 3 months of exposure to sodium metavanadate via drinking water. No increases in the frequencies of micronucleated reticulocytes or micronucleated mature erythrocytes were observed in male or female mice exposed to sodium metavanadate in drinking water for 3 months (Table D-4). However, significant increases in the percentage of reticulocytes were observed for both male and female mice, indicating that exposure to sodium metavanadate had a stimulatory effect on erythropoiesis.

In the vanadyl sulfate study, male and female rats did not show an increase in micronucleated reticulocytes (Table D-5). No significant changes in the percentage of reticulocytes were observed in male or female rats, suggesting that vanadyl sulfate exposure did not affect erythropoiesis. No significant increases in the frequencies of micronucleated reticulocytes or micronucleated mature erythrocytes were observed in male or female mice administered vanadyl sulfate in drinking water for 3 months (Table D-6). However, significant increases in the percentage of reticulocytes were observed for male and female mice, indicating that exposure to vanadyl sulfate had a stimulatory effect on erythropoiesis.

Table D-3 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male and Female Rats in the Three-month Drinking Water Study of Sodium Metavanadate^a^

| Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)^b^ | P Value^c^
Male
Exposure Concentration (mg/L)
0 | 5 | 0.468 ± 0.049 | | 0.082 ± 0.019 | | 0.934 ± 0.210
31.3 | 5 | 0.440 ± 0.068 | 1.0000 | 0.074 ± 0.027 | 1.0000 | 1.218 ± 0.046 | 1.0000
62.5 | 5 | 0.550 ± 0.065 | 1.0000 | 0.115 ± 0.018 | 1.0000 | 1.269 ± 0.080 | 0.9191
125 | 5 | 0.539 ± 0.103 | 1.0000 | 0.132 ± 0.018 | 0.7439 | 1.274 ± 0.053 | 0.6569
250 | 5 | 0.490 ± 0.090 | 1.0000 | 0.198 ± 0.036 | 0.1015 | 1.385 ± 0.127 | 0.0978
500 | 5 | 0.750 ± 0.092 | 0.0751 | 0.292 ± 0.037 | 0.0044 | 1.636 ± 0.082 | 0.0016
Trend^d^ | | p = 0.0204 | | p < 0.001 | | p < 0.001
Female
Exposure Concentration (mg/L)
0 | 5 | 0.620 ± 0.070 | | 0.085 ± 0.010 | | 1.132 ± 0.095
31.3 | 5 | 0.650 ± 0.097 | 1.0000 | 0.074 ± 0.008 | 1.0000 | 1.193 ± 0.147 | 1.0000
62.5 | 5 | 0.660 ± 0.135 | 1.0000 | 0.116 ± 0.026 | 1.0000 | 1.196 ± 0.080 | 1.0000
125 | 5 | 0.620 ± 0.049 | 1.0000 | 0.151 ± 0.038 | 0.4031 | 1.201 ± 0.097 | 1.0000
250 | 5 | 0.490 ± 0.110 | 1.0000 | 0.106 ± 0.024 | 1.0000 | 1.319 ± 0.149 | 0.7538
500 | 5 | 0.710 ± 0.139 | 1.0000 | 0.206 ± 0.029 | 0.0269 | 1.336 ± 0.099 | 0.4233
Trend | | p = 0.6294 | | p = 0.0031 | | p = 0.0671

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at Integrated Laboratory Systems, LLC.

^b^ Data are presented as mean ± standard error.

^c^ Pairwise comparisons with the vehicle control group performed using the Dunn test (p ≤ 0.025).

^d^ Exposure-related trends evaluated by linear regression or the Jonckheere test (p ≤ 0.025).

Table D-4 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male and Female Mice in the Three-month Drinking Water Study of Sodium Metavanadate^a^

| Number of Mice with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)^b^ | P Value^c^
Male
Exposure Concentration (mg/L)
0 | 5 | 2.840 ± 0.118 | | 1.564 ± 0.011 | | 1.546 ± 0.054
31.3 | 5 | 3.050 ± 0.152 | 1.0000 | 1.527 ± 0.027 | 1.0000 | 1.399 ± 0.043 | 1.0000
62.5 | 5 | 2.608 ± 0.190 | 1.0000 | 1.523 ± 0.051 | 1.0000 | 1.588 ± 0.038 | 1.0000
125 | 5 | 2.910 ± 0.222 | 1.0000 | 1.557 ± 0.034 | 1.0000 | 1.851 ± 0.067 | 0.6122
250 | 5 | 2.480 ± 0.290 | 1.0000 | 1.471 ± 0.047 | 1.0000 | 2.130 ± 0.065 | 0.0660
500 | 5 | 2.430 ± 0.133 | 1.0000 | 1.426 ± 0.018 | 1.0000 | 2.699 ± 0.066 | 0.0032
Trend^d^ | | p = 0.9693 | | p = 0.9941 | | p < 0.001
Female
Exposure Concentration (mg/L)
0 | 5 | 2.190 ± 0.196 | | 0.969 ± 0.022 | | 1.843 ± 0.092
31.3 | 5 | 1.990 ± 0.163 | 1.0000 | 1.004 ± 0.010 | 0.5897 | 1.408 ± 0.167 | 1.0000
62.5 | 5 | 1.760 ± 0.130 | 1.0000 | 1.015 ± 0.023 | 0.2850 | 1.677 ± 0.215 | 1.0000
125 | 5 | 1.690 ± 0.207 | 1.0000 | 0.995 ± 0.018 | 1.0000 | 2.276 ± 0.177 | 1.0000
250 | 5 | 2.190 ± 0.051 | 1.0000 | 0.965 ± 0.032 | 1.0000 | 2.879 ± 0.080 | 0.2410
500 | 5 | 1.520 ± 0.177 | 1.0000 | 0.969 ± 0.026 | 1.0000 | 3.259 ± 0.073 | 0.0181
Trend | | p = 0.9596 | | p = 0.6878 | | p < 0.001

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte

^a^ Study was performed at Integrated Laboratory Systems, LLC.

^b^ Data are presented as mean ± standard error.

^c^ Pairwise comparisons with the vehicle control group performed using the Dunn test (p ≤ 0.025).

^d^ Exposure-related trends evaluated by linear regression or the Jonckheere test (p ≤ 0.025).

Table D-5 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male and Female Rats in the Three-month Drinking Water Study of Vanadyl Sulfate^a^

| Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)^b^ | P Value^c^
Male
Exposure Concentration (mg/L)
0 | 5 | 0.904 ± 0.179 | | 0.345 ± 0.101 | | 1.204 ± 0.142
21.0 | 5 | 1.071 ± 0.202 | 1.0000 | 0.332 ± 0.126 | 1.0000 | 1.085 ± 0.046 | 1.0000
41.9 | 5 | 0.810 ± 0.168 | 1.0000 | 0.415 ± 0.099 | 1.0000 | 1.129 ± 0.066 | 1.0000
83.8 | 5 | 0.870 ± 0.155 | 1.0000 | 0.243 ± 0.083 | 1.0000 | 1.219 ± 0.021 | 1.0000
168 | 5 | 0.830 ± 0.151 | 1.0000 | 0.332 ± 0.065 | 1.0000 | 1.252 ± 0.088 | 1.0000
335 | 5 | 0.760 ± 0.051 | 1.0000 | 0.278 ± 0.041 | 1.0000 | 1.368 ± 0.026 | 0.4568
Trend^d^ | | p = 0.7827 | | p = 0.5932 | | p = 0.0069
Female
Exposure Concentration (mg/L)
0 | 5 | 0.640 ± 0.051 | | 0.222 ± 0.045 | | 0.948 ± 0.129
21.0 | 5 | 0.946 ± 0.096 | 0.1049 | 0.181 ± 0.038 | 1.0000 | 0.920 ± 0.053 | 1.0000
41.9 | 5 | 0.680 ± 0.106 | 1.0000 | 0.211 ± 0.057 | 1.0000 | 1.218 ± 0.060 | 0.1861
83.8 | 5 | 0.930 ± 0.041 | 0.0880 | 0.319 ± 0.075 | 1.0000 | 1.001 ± 0.076 | 1.0000
168 | 5 | 0.920 ± 0.142 | 0.2182 | 0.315 ± 0.102 | 1.0000 | 1.041 ± 0.039 | 1.0000
335 | 5 | 0.620 ± 0.150 | 1.0000 | 0.196 ± 0.039 | 1.0000 | 1.143 ± 0.039 | 0.7041
Trend | | p = 0.3786 | | p = 0.3517 | | p = 0.0850

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at Integrated Laboratory Systems, LLC.

^b^ Data are presented as mean ± standard error.

^c^ Pairwise comparisons with the vehicle control group performed using the Dunn test (p ≤ 0.025).

^d^ Exposure-related trends evaluated by linear regression or the Jonckheere test (p ≤ 0.025).

Table D-6 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male and Female Mice in the Three-month Drinking Water Study of Vanadyl Sulfate^a^

| Number of Mice with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)^b^ | P Value^c^
Male
Exposure Concentration (mg/L)
0 | 5 | 3.120 ± 0.141 | | 1.595 ± 0.037 | | 1.503 ± 0.048
21.0 | 5 | 2.850 ± 0.329 | 1.0000 | 1.671 ± 0.062 | 0.8758 | 1.675 ± 0.081 | 0.9798
41.9 | 5 | 2.360 ± 0.193 | 1.0000 | 1.576 ± 0.062 | 1.0000 | 1.537 ± 0.031 | 1.0000
83.8 | 5 | 2.620 ± 0.252 | 1.0000 | 1.487 ± 0.118 | 1.0000 | 1.767 ± 0.069 | 0.2030
168 | 5 | 2.380 ± 0.119 | 1.0000 | 1.580 ± 0.033 | 1.0000 | 1.775 ± 0.087 | 0.2030
335 | 5 | 2.440 ± 0.083 | 1.0000 | 1.660 ± 0.054 | 1.0000 | 2.024 ± 0.049 | 0.0016
Trend^d^ | | p = 0.9948 | | p = 0.4495 | | p < 0.001
Female
Exposure Concentration (mg/L)
0 | 5 | 2.710 ± 0.277 | | 1.265 ± 0.054 | | 1.296 ± 0.135
21.0 | 5 | 1.830 ± 0.062 | 1.0000 | 1.057 ± 0.041 | 1.0000 | 1.821 ± 0.147 | 0.3348
41.9 | 5 | 2.420 ± 0.292 | 1.0000 | 1.201 ± 0.092 | 1.0000 | 1.537 ± 0.180 | 1.0000
83.8 | 5 | 1.970 ± 0.176 | 1.0000 | 1.137 ± 0.049 | 1.0000 | 1.741 ± 0.199 | 0.4568
168 | 5 | 2.020 ± 0.175 | 1.0000 | 1.187 ± 0.034 | 1.0000 | 1.902 ± 0.120 | 0.1182
335 | 5 | 2.400 ± 0.373 | 1.0000 | 1.310 ± 0.082 | 1.0000 | 2.267 ± 0.327 | 0.0181
Trend | | p = 0.6553 | | p = 0.1871 | | p = 0.0031

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at Integrated Laboratory Systems, LLC.

^b^ Data are presented as mean ± standard error.

^c^ Pairwise comparisons with the vehicle control group performed using the Dunn test (p ≤ 0.025).

^d^ Exposure-related trends evaluated by linear regression or the Jonckheere test (p ≤ 0.025).