# Appendix C Sentinel Animal Program

## C.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that might affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or exposed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

In these toxicity studies, blood samples were collected from each sentinel animal and allowed to clot, and the serum was separated. Additionally, fecal samples were collected and tested for endoparasites and Helicobacter species. All samples were processed appropriately with serology testing performed in-house or by IDEXX BioResearch (formerly Rodent Animal Diagnostic Laboratory [RADIL], University of Missouri), Columbia, MO, for determination of the presence of pathogens. Evaluation for endo- and ectoparasites was performed in-house by the testing laboratory.

The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed (Table C-1, Table C-2, Table C-3, Table C-4).

## C.2 Results

Rats: All test results were negative.

Mice: All test results were negative.

Table C-1 Methods and Results for Sentinel Animal Testing in Male and Female Rats in the Three-month Study of Sodium Metavanadate

Three-month Study
Collection Timepoints | Quarantine^a^ | 4 Weeks^b^ | Study Termination
Number Examined (Males/Females) | 0/10 | 5/5 | 5/5
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Kilham rat virus (KRV) | − | − | −
Mycoplasma pulmonis | − | − | −
Pneumocystis carinii | NT | NT | −
Pneumonia virus of mice (PVM) | − | − | −
Rat coronavirus/sialodacryoadenitis virus (RCV/SDA) | − | − | −
Rat minute virus (RMV) | − | − | −
Rat parvo virus (RPV) | − | − | −
Rat theilovirus (RTV) | − | − | −
Sendai | − | − | −
Theiler’s murine encephalomyelitis virus (TMEV) | − | − | −
Toolan’s H-1 | − | − | −
In-house Evaluation
Parasite evaluation (evaluation of cecal contents and perianal surface) | − | − | NT

− = negative; NT = not tested.

^a^ Age matched nonpregnant females.

^b^ F_1_ sentinel animals tested 4 weeks after study start.

Table C-2 Methods and Results for Sentinel Animal Testing in Male and Female Mice in the Three-month Study of Sodium Metavanadate

Three-month Study
Collection Timepoints | Quarantine | 4 Weeks | Study Termination
Number Examined (Males/Females) | 5/5 | 5/5 | 5/5
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Ectromelia virus | − | − | −
Epizootic diarrhea of infant mice (EDIM) | − | − | −
Lymphocytic choriomeningitis virus (LCMV) | − | − | −
Mycoplasma pulmonis | − | − | −
Mouse hepatitis virus (MHV) | − | − | −
Mouse norovirus (MNV) | − | − | −
Mouse parvovirus (MPV) | − | − | −
Minute virus of mice (MVM) | − | − | −
Pneumonia virus of mice (PVM) | − | − | −
Reovirus (REO3) | − | − | −
Rat theilovirus (RTV) | − | − | −
Sendai | − | − | −
Theiler’s murine encephalomyelitis virus (TMEV) GDVII | − | − | −
In-house Evaluation
Parasite evaluation (evaluation of cecal contents and perianal surface) | − | − | NT

− = negative; NT = not tested.

Table C-3 Methods and Results for Sentinel Animal Testing in Male and Female Rats in the Three-month Study of Vanadyl Sulfate

Three-month Study
Collection Timepoints | Quarantine^a^ | 4 Weeks^b^ | Study Termination
Number Examined (Males/Females) | 0/10 | 5/5 | 5/5
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Kilham rat virus (KRV) | − | − | −
Mycoplasma pulmonis | − | − | −
Pneumonia virus of mice (PVM) | − | − | −
Rat coronavirus/sialodacryoadenitis virus (RCV/SDA) | − | − | −
Rat minute virus (RMV) | − | − | −
Rat parvo virus (RPV) | − | − | −
Rat theilovirus (RTV) | − | − | −
Sendai | − | − | −
Theiler’s murine encephalomyelitis virus (TMEV) | − | − | −
Toolan’s H-1 | − | − | −
In-house Evaluation
Parasite evaluation (evaluation of cecal contents and perianal surface) | − | − | NT

− = negative; NT = not tested.

^a^ Age matched nonpregnant females.

^b^ F_1_ sentinel animals tested 4 weeks after study start.

Table C-4 Methods and Results for Sentinel Animal Testing in Male and Female Mice in the Three-month Study of Vanadyl Sulfate

Three-month Study
Collection Timepoints | Quarantine | 4 Weeks | 7 Weeks | Study Termination
Number Examined (Males/Females) | 5/5 | 5/5 | 1/0 | 5/5
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Ectromelia virus | − | − | − | −
Epizootic diarrhea of infant mice (EDIM) | − | − | − | −
Lymphocytic choriomeningitis virus (LCMV) | − | − | − | −
Mycoplasma pulmonis | − | − | − | −
Mouse hepatitis virus (MHV) | − | − | − | −
Mouse norovirus (MNV) | − | − | − | −
Mouse parvovirus (MPV) | − | − | − | −
Minute virus of mice (MVM) | − | − | − | −
Pneumonia virus of mice (PVM) | − | − | − | −
Reovirus (REO3) | − | − | − | −
Rat theilovirus (RTV) | − | − | − | −
Sendai | − | − | − | −
Theiler’s murine encephalomyelitis virus (TMEV) GDVII | − | − | − | −
In-house Evaluation
Parasite evaluation (evaluation of cecal contents and perianal surface) | − | − | NT | NT

− = negative; NT = not tested.