# Appendix B Ingredients, Nutrient Composition, and Contaminant Levels in NIH-07 and NTP-2000 Rat and Mouse Ration

## B.1 NIH-07 Feed

Table B-1 Ingredients of NIH-07 Rat Ration

Ingredients | Percent by Weight
Ground Hard Winter Wheat | 23.0
Ground #2 Yellow Shelled Corn | 24.25
Wheat Middlings | 10.0
Oat Hulls | 0.0
Alfalfa Meal (Dehydrated, 17% Protein) | 4.0
Purified Cellulose | 0.0
Soybean Meal (47% Protein) | 12.0
Fish Meal (62% Protein) | 10.0
Corn Oil (without Preservatives) | 0.0
Soy Oil (without Preservatives) | 2.5
Dried Brewer’s Yeast | 2.0
Calcium Carbonate (USP) | 0.5
Vitamin Premix^a^ | 0.25
Mineral Premix^b^ | 0.15
Calcium Phosphate, Dibasic (USP) | 1.25
Sodium Chloride | 0.5
Choline Chloride (70% Choline) | 0.10
Dried Skim Milk | 5.0
Dried Molasses | 1.5
Corn Gluten Meal (60% Protein) | 3.0
Methionine | 0.0

USP = United States Pharmacopeia.

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table B-2 Vitamins and Minerals in NIH-07 Rat Ration

| Amount^a^ | Source
Vitamins
Vitamin A | 6,062 IU | Stabilized vitamin A palmitate or acetate
Vitamin D | 5,070 IU | D-activated animal sterol
Vitamin K | 3.1 mg | Menadione sodium bisulfite complex
Vitamin E | 22 IU | α-Tocopheryl Acetate
Niacin | 33 mg | –
Folic Acid | 2.4 mg | –
d-Pantothenic Acid | 19.8 mg | d-Calcium pantothenate
Riboflavin | 3.8 mg | –
Thiamine | 11 mg | Thiamine mononitrate
B_12_ | 50 µg | –
Pyridoxine | 6.5 mg | Pyridoxine hydrochloride
Biotin | 0.15 mg | d-Biotin
Minerals
Iron | 132 mg | Iron sulfate
Zinc | 18 mg | Zinc oxide
Manganese | 66 mg | Manganese oxide
Copper | 4.4 mg | Copper sulfate
Iodine | 2.0 mg | Calcium iodate
Cobalt | 0.44 mg | Cobalt carbonate

^a^ Per kg of finished diet.

Table B-3 Nutrient Composition of NIH-07 Rat Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 22.87 ± 0.208 | 22.7–23.1 | 3
Crude Fat (% by Weight) | 5.2 ± 0.0 | 5.4–5.2 | 3
Crude Fiber (% by Weight) | 2.98 ± 0.437 | 2.48–3.27 | 3
Ash (% by Weight) | 6.41 ± 0.086 | 6.32–6.49 | 3
Amino Acids (% of Total Diet)
Arginine | 1.278 ± 0.343 | 0.258–1.49 | 11
Cystine | 0.307 ± 0.059 | 0.153–0.372 | 11
Glycine | 1.065 ± 0.289 | 0.217–1.31 | 11
Histidine | 0.482 ± 0.121 | 0.125–0.553 | 11
Isoleucine | 0.914 ± 0.233 | 0.214–1.03 | 11
Leucine | 1.873 ± 0.485 | 0.423–2.13 | 11
Lysine | 1.140 ± 0.345 | 0.111–1.32 | 11
Methionine | 0.453 ± 0.117 | 0.102–0.515 | 11
Phenylalanine | 1.023 ± 0.245 | 0.286–1.12 | 11
Threonine | 0.850 ± 0.228 | 0.168–0.961 | 11
Tryptophan | 0.259 ± 0.064 | 0.076–0.326 | 11
Tyrosine | 0.801 ± 0.200 | 0.209–0.894 | 11
Valine | 1.055 ± 0.264 | 0.262–1.17 | 11
Essential Fatty Acids (% of Total Diet)
Linoleic | 2.436 ± 0.489 | 0.199–3.77 | 11
Linolenic | 0.367 ± 0.397 | 0.214–1.56 | 11
Vitamins
Vitamin A (IU/kg) | 4,180 ± 46.03 | 3,730–4,650 | 3
α-Tocopherol (ppm) | 6,097 ± 20,067 | 31.36–66,600 | 11
Thiamine (ppm)^a^ | 14.3 ± 1.473 | 12.6–15.2 | 3
Riboflavin (ppm) | 13.54 ± 4.438 | 4.2–19.8 | 11
Niacin (ppm) | 95.02 ± 16.30 | 51.9–112.0 | 11
Pantothenic Acid (ppm) | 40.69 ± 12.76 | 3.8–51.1 | 11
Pyridoxine (ppm)^a^ | 11.74 ± 4.81 | 0.42–19.7 | 11
Folic Acid (ppm) | 2.38 ± 0.571 | 1.37–3.09 | 11
Biotin (ppm) | 0.300 ± 0.187 | 0.0–0.638 | 11
B_12_ (ppb) | 45.27 ± 15.14 | 4.0–61.6 | 11
Choline (as Chloride) (ppm) | 1,719.0 ± 386.0 | 700.0–2,200.0 | 11
Minerals
Calcium (%) | 1.14 ± 0.055 | 1.09–1.2 | 3
Phosphorus (%) | 0.94 ± 0.069 | 0.862–0.992 | 3
Potassium (%) | 0.762 ± 0.226 | 0.088–0.88 | 11
Chloride (%) | 0.656 ± 0.102 | 0.411–0.8 | 11
Sodium (%) | 0.409 ± 0.112 | 0.318–0.721 | 11
Magnesium (%) | 0.171 ± 0.053 | 0.0162–0.218 | 11
Iron (ppm) | 353.3 ± 117.5 | 35.7–469.0 | 11
Manganese (ppm) | 82.88 ± 27.28 | 3.53–104.0 | 11
Zinc (ppm) | 58.75 ± 20.3 | 4.74–89.2 | 11
Copper (ppm) | 12.91 ± 4.73 | 0.683–21.1 | 11
Iodine (ppm) | 1.647 ± 1.088 | 0.0–3.45 | 11
Chromium (ppm) | 3.95 ± 0.035 | 3.89–4.0 | 9
Cobalt (ppm) | 0.470 ± 0.296 | 0.01–0.963 | 11

^a^ As hydrochloride.

Table B-4 Contaminant Levels in NIH-07 Rat Ration

| Mean ± Standard Deviation | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.481 ± 0.006 | 0.474–0.486 | 3
Cadmium (ppm) | 0.087 ± 0.004 | 0.083–0.09 | 3
Lead (ppm) | 0.084 ± 0.007 | 0.077–0.091 | 3
Mercury (ppm) | 0.017 ± 0.003 | 0.014–0.02 | 3
Selenium (ppm) | 0.286 ± 0.020 | 0.264–0.304 | 3
Aflatoxins (ppb)^a^ | <5.0 | – | 3
Nitrate Nitrogen (ppm)^b^ | 9.54 ± 1.11 | 8.71–10.8 | 3
Nitrite Nitrogen (ppm)^a,b^ | <0.61 | – | 3
BHA (ppm)^a,c^ | <1.0 | – | 3
BHT (ppm)^a,c^ | <1.0 | – | 3
Aerobic Plate Count (CFU/g) | <10.0 | – | 3
Coliform (MPN/g) | <3.0 | – | 3
Escherichia coli (MPN/g)^a^ | <3.0 | – | 3
Salmonella sp. (MPN/g) | Negative | – | 3
Total Nitrosamines (ppb)^d^ | 9.67 ± 2.53 | 6.8–11.6 | 3
N-Nitrosodimethylamine (ppb)^d^ | 6.95 ± 0.919 | 6.3–7.6 | 3
N-Nitrosopyrrolidine (ppb)^d^ | 5.03 ± 1.54 | 4.0–6.8 | 3
Pesticides (ppm)
α-BHC^a^ | <0.01 | – | 3
β-BHC^a^ | <0.02 | – | 3
γ-BHC^a^ | <0.01 | – | 3
δ-BHC^a^ | <0.01 | – | 3
Heptachlor^a^ | <0.01 | – | 3
Aldrin^a^ | <0.01 | – | 3
Heptachlor Epoxide^a^ | <0.01 | – | 3
DDE^a^ | <0.01 | – | 3
DDD^a^ | <0.01 | – | 3
DDT^a^ | <0.01 | – | 3
HCB^a^ | <0.01 | – | 3
Mirex^a^ | <0.01 | – | 3
Methoxychlor^a^ | <0.05 | – | 3
Dieldrin^a^ | <0.01 | – | 3
Endrin^a^ | <0.01 | – | 3
Telodrin^a^ | <0.01 | – | 3
Chlordane^a^ | <0.05 | – | 3
Toxaphene^a^ | <0.10 | – | 3
Estimated PCBs^a^ | <0.20 | – | 3
Ronnel^a^ | <0.01 | – | 3
Ethion^a^ | <0.02 | – | 3
Trithion^a^ | <0.05 | – | 3
Diazinon^a^ | <0.10 | – | 3
Methyl Chlorpyrifos | 0.071 ± 0.077 | 0.02–0.16 | 3
Methyl Parathion^a^ | <0.02 | – | 3
Ethyl Parathion^a^ | <0.02 | – | 3
Malathion | 0.0835 ± 0.055 | 0.0285–0.138 | 3
Endosulfan I^a^ | <0.01 | – | 3
Endosulfan II^a^ | <0.01 | – | 3
Endosulfane Sulfate^a^ | <0.03 | – | 3

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.

## B.2 NTP-2000 Feed

Table B-5 Ingredients of NTP-2000 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground Hard Winter Wheat | 23.00
Ground #2 Yellow Shelled Corn | 22.44
Wheat Middlings | 15.0
Oat Hulls | 8.5
Alfalfa Meal (Dehydrated, 17% Protein) | 7.5
Purified Cellulose | 5.5
Soybean Meal (49% Protein) | 4.0
Fish Meal (60% Protein) | 4.0
Corn Oil (without Preservatives) | 3.0
Soy Oil (without Preservatives) | 3.0
Dried Brewer’s Yeast | 1.0
Calcium Carbonate (USP) | 0.9
Vitamin Premix^a^ | 0.5
Mineral Premix^b^ | 0.5
Calcium Phosphate, Dibasic (USP) | 0.4
Sodium Chloride | 0.3
Choline Chloride (70% Choline) | 0.26
Methionine | 0.2

USP = United States Pharmacopeia.

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table B-6 Vitamins and Minerals in NTP-2000 Rat and Mouse Ration

| Amount^a^ | Source
Vitamins
Vitamin A | 4,000 IU | Stabilized vitamin A palmitate or acetate
Vitamin D | 1,000 IU | D-activated animal sterol
Vitamin K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl Acetate | 100 IU | –
Niacin | 23 mg | –
Folic Acid | 1.1 mg | –
d-Pantothenic Acid | 10 mg | d-Calcium pantothenate
Riboflavin | 3.3 mg | –
Thiamine | 4 mg | Thiamine mononitrate
B_12_ | 52 µg | –
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | α-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

^a^ Per kg of finished diet.

Table B-7 Nutrient Composition of NTP-2000 Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 14.7 ± 0.454 | 14.0–15.3 | 11
Crude Fat (% by Weight) | 8.25 ± 0.202 | 7.9–8.5 | 11
Crude Fiber (% by Weight) | 9.54 ± 0.304 | 9.08–10.1 | 11
Ash (% by Weight) | 4.95 ± 0.101 | 4.77–5.09 | 11
Amino Acids (% of Total Diet)
Arginine | 0.806 ± 0.073 | 0.67–0.97 | 31
Cystine | 0.220 ± 0.021 | 0.15–0.25 | 31
Glycine | 0.702 ± 0.037 | 0.62–0.8 | 31
Histidine | 0.341 ± 0.068 | 0.27–0.68 | 31
Isoleucine | 0.548 ± 0.039 | 0.43–0.66 | 31
Leucine | 1.095 ± 0.061 | 0.96–1.24 | 31
Lysine | 0.070 ± 0.101 | 0.31–0.86 | 31
Methionine | 0.409 ± 0.040 | 0.26–0.49 | 31
Phenylalanine | 0.623 ± 0.045 | 0.471–0.72 | 31
Threonine | 0.513 ± 0.040 | 0.43–0.61 | 31
Tryptophan | 0.156 ± 0.026 | 0.11–0.2 | 31
Tyrosine | 0.425 ± 0.064 | 0.28–0.54 | 31
Valine | 0.666 ± 0.038 | 0.55–0.73 | 31
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.936 ± 0.229 | 3.49–4.55 | 31
Linolenic | 0.306 ± 0.030 | 0.21–0.368 | 31
Vitamins
Vitamin A (IU/kg) | 3,060 ± 101.1 | 2,090–5,130 | 11
α-Tocopherol (ppm) | 2,300 ± 12,398 | 13.6–69,100 | 31
Thiamine (ppm)^a^ | 7.65 ± 0.530 | 7.0–8.6 | 11
Riboflavin (ppm) | 8.19 ± 2.747 | 4.2–17.5 | 31
Niacin (ppm) | 80.10 ± 9.733 | 66.4–107.0 | 31
Pantothenic Acid (ppm) | 26.28 ± 10.69 | 17.4–81.0 | 31
Pyridoxine (ppm)^a^ | 9.657 ± 2.013 | 6.44–14.3 | 31
Folic Acid (ppm) | 1.59 ± 0.434 | 1.15–3.27 | 31
Biotin (ppm) | 0.331 ± 0.096 | 0.2–0.704 | 31
B_12_ (ppb) | 50.15 ± 33.77 | 18.3–174.0 | 31
Choline (as Chloride) (ppm) | 2,553 ± 632 | 1,160–3,790 | 31
Minerals
Calcium (%) | 0.890 ± 0.051 | 0.832–0.976 | 11
Phosphorus (%) | 0.558 ± 0.023 | 0.522–0.596 | 11
Potassium (%) | 0.666 ± 0.034 | 0.563–0.733 | 31
Chloride (%) | 0.389 ± 0.044 | 0.3–0.517 | 31
Sodium (%) | 0.193 ± 0.027 | 0.153–0.283 | 31
Magnesium (%) | 0.217 ± 0.053 | 0.185–0.49 | 31
Iron (ppm) | 190.0 ± 35.69 | 135–311 | 31
Manganese (ppm) | 49.95 ± 9.12 | 21.0–73.1 | 31
Zinc (ppm) | 56.51 ± 24.88 | 42.5–184 | 31
Copper (ppm) | 7.61 ± 2.42 | 3.21–16.3 | 31
Iodine (ppm) | 0.530 ± 0.230 | 0.0–1.0 | 31
Chromium (ppm) | 1.213 ± 1.25 | 0.33–3.97 | 31
Cobalt (ppm) | 0.216 ± 0.148 | 0.086–0.864 | 29

^a^ As hydrochloride.

Table B-8 Contaminant Levels in NTP-2000 Rat and Mouse Ration

| Mean ± Standard Deviation | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.241 ± 0.024 | 0.211–0.287 | 11
Cadmium (ppm) | 0.051 ± 0.003 | 0.045–0.056 | 11
Lead (ppm) | 0.093 ± 0.031 | 0.066–0.158 | 11
Mercury (ppm) | 0.010 ± 0.0 | 0.009–0.01 | 11
Selenium (ppm) | 0.163 ± 0.023 | 0.134–0.201 | 11
Aflatoxins (ppb)^a^ | <5.0 | – | 11
Nitrate Nitrogen (ppm)^b^ | 11.67 ± 0.023 | 9.02–16.58 | 11
Nitrite Nitrogen (ppm)^a,b^ | <0.61 | – | 11
BHA (ppm)^a,c^ | <1.0 | – | 11
BHT (ppm)^a,c^ | <1.0 | – | 11
Aerobic Plate Count (CFU/g) | 25.45 ± 51.26 | 10.0–180.0 | 11
Coliform (MPN/g) | <3.0 | – | 11
Escherichia coli (MPN/g)^a^ | <3.0 | – | 11
Salmonella sp. (MPN/g) | Negative | – | 11
Total Nitrosamines (ppb)^d^ | 8.4 ± 3.8 | 2.4–14.2 | 11
N-Nitrosodimethylamine (ppb)^d^ | 2.9 ± 1.9 | 1.0–5.0 | 11
N-Nitrosopyrrolidine (ppb)^d^ | 5.5 ± 2.8 | 1.2–9.5 | 11
Pesticides (ppm)
α-BHC^a^ | <0.01 | – | 11
β-BHC^a^ | <0.02 | – | 11
γ-BHC^a^ | <0.01 | – | 11
δ-BHC^a^ | <0.01 | – | 11
Heptachlor^a^ | <0.01 | – | 11
Aldrin^a^ | <0.01 | – | 11
Heptachlor Epoxide^a^ | <0.01 | – | 11
DDE^a^ | <0.01 | – | 11
DDD^a^ | <0.01 | – | 11
DDT^a^ | <0.01 | – | 11
HCB^a^ | <0.01 | – | 11
Mirex^a^ | <0.01 | – | 11
Methoxychlor^a^ | <0.05 | – | 11
Dieldrin^a^ | <0.01 | – | 11
Endrin^a^ | <0.01 | – | 11
Telodrin^a^ | <0.01 | – | 11
Chlordane^a^ | <0.05 | – | 11
Toxaphene^a^ | <0.01 | – | 11
Estimated PCBs^a^ | <0.20 | – | 11
Ronnel^a^ | <0.01 | – | 11
Ethion^a^ | <0.02 | – | 11
Trithion^a^ | <0.05 | – | 11
Diazinon^a^ | <0.10 | – | 11
Methyl Chlorpyrifos | 0.172 ± 0.105 | 0.0–0.36 | 11
Ethyl Chlorpyrifos | 0.009 ± 0.013 | 0.0–0.025 | 11
Methyl Pirimiphos | 0.013 ± 0.017 | 0.0–0.05 | 11
Methyl Parathion^a^ | <0.02 | – | 11
Ethyl Parathion^a^ | <0.02 | – | 11
Malathion | 0.180 ± 0.147 | 0.02–0.585 | 11
Endosulfan I^a^ | <0.01 | – | 11
Endosulfan II^a^ | <0.01 | – | 11
Endosulfane Sulfate^a^ | <0.03 | – | 11

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.