# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization

### A.1.1 Sodium Metavanadate

Sodium metavanadate was obtained from MP Biomedicals (Irvine, CA) in a single lot (8579K). Identity, purity, and stability analyses were conducted at the Battelle analytical chemistry laboratory (Columbus, OH). Reports on analyses performed in support of the sodium metavanadate studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

Lot 8579K, a white-to-yellow powder, was identified as sodium metavanadate using infrared (IR) spectroscopy and X-ray diffraction (XRD). The IR spectrum was consistent with the library spectra (Figure A-1).^89-91^ XRD analysis indicated that the sample was anhydrous sodium metavanadate because the indexed pattern matched the library pattern for metamunirite (NaVO_3_) (Figure A-2).^92^

Moisture content was determined by weight loss on drying, Karl Fischer titration, and thermal gravimetric analysis (TGA). Moisture content by weight loss on drying was 0.2%. Under ambient conditions, the dried sample reabsorbed that same amount of water. Karl Fischer titration by Galbraith Laboratories, Inc. (Knoxville, TN) yielded a water content of 0.16%. TGA resulted in a measured water content of 0.25%.

Elemental analysis to aid in chemical identity confirmation and purity analysis was performed with scanning electron microscope (SEM) energy dispersive X-ray spectroscopy (EDS), proton-induced X-ray emission (PIXE) spectroscopy, and inductively coupled plasma (ICP) atomic emission spectroscopy (AES). The SEM-EDS spectrum was consistent with an inorganic compound consisting of vanadium (46.3%), sodium (28.5%), and oxygen (25.2%). No impurities were detected by SEM-EDS. The results for vanadium and sodium were higher compared to the theoretical values (41.78% and 18.86%, respectively). PIXE analysis by Elemental Analysis, Inc. (Lexington, KY) indicated the sample contains 34.9% vanadium, 20.5% sodium, and 44.6% oxygen. The percentage of vanadium was lower than the theoretical and the certificate of analysis (41.52%) values, and the percentage of sodium was higher than the theoretical value. No significant inorganic impurities were detected by PIXE. ICP-AES found the sample contained 41.3% vanadium and 18.9% sodium, which agreed with the theoretical and certificate of analysis values for sodium metavanadate.

Analysis using high-performance liquid chromatography (HPLC) with charged aerosol detection (CAD) (Table A-1, System A) showed a single peak with no reportable impurities. The volatile content was determined by gas chromatography (GC) with flame ionization detection (FID) and electron capture detection (ECD) (Table A-2, System G) using four halogenated and six nonhalogenated standards. No volatiles were detected with GC. The overall purity of lot 8579K was determined to be >99%.

Accelerated stability studies were conducted using HPLC/CAD (Table A-1, System A). Lot 8579K was stored at refrigerated (5°C), room (25°C), and elevated (60°C) temperatures for 2 weeks and then analyzed for purity relative to a frozen (−20°C) sample. Stability was confirmed for at least 2 weeks when stored sealed in amber glass at temperatures of ≤60°C. Three containers of lot 8579K were received and homogenized by mixing all contents in a 1-ft^3^ Patterson-Kelley twin-shell blender for approximately 15 minutes. The bulk chemical was stored at room temperature in amber plastic bottles. Reanalysis of the bulk chemical using HPLC/CAD (Table A-1, System B) was conducted before, during, and after the studies by the analytical chemistry laboratory. No significant differences were detected in the purities between the bulk test article and frozen reference standard during reanalysis.

### A.1.2 Vanadyl Sulfate

Vanadyl sulfate was obtained from Noah Technologies Corporation (San Antonio, TX) in a single lot (0210324/1.1). The manufacturer’s certificate of analysis for vanadyl sulfate provided the material as vanadyl sulfate hydrate with an unspecified number of water molecules (VOSO_4_·xH_2_O) but provided the CASRN for the anhydrous form because hydrated forms do not have a single CASRN. The chemical name vanadyl sulfate and the corresponding CASRN 27774-13-6 were used for the purpose of reporting the study. Identity, purity, and stability analyses were conducted at the Battelle analytical chemistry laboratory (Columbus, OH). Reports on analyses performed in support of the vanadyl sulfate studies are on file at NIEHS.

Lot 0210324/1.1, a blue, dusty powder, was identified as vanadyl sulfate using IR and XRD. The IR spectrum was consistent with the reference spectrum for vanadyl sulfate trihydrate from the Sadtler Inorganics Library (SL No. 1424) (Figure A-3).^93^ The major absorption bands identified the presence of hydrated vanadyl sulfate in the test article. The XRD analysis indicated that the sample contained vanadyl sulfate in at least two hydrated crystalline phases: (VO)(SO_4_)·5H_2_O and (VO)(SO_4_)·3H_2_O (Figure A-4 and Figure A-5).^92^ Anhydrous vanadyl sulfate was not detected by XRD.

Moisture content was determined by weight loss on drying, Karl Fischer titration, and TGA. Moisture content of the test article measured by weight loss on drying was 21.8%. Under ambient conditions, the dried sample reabsorbed 3.6% water. Karl Fischer titration by Galbraith Laboratories, Inc. (Knoxville, TN) yielded a water content of 22.8%. TGA resulted in a measured water content of 32.9%, which likely corresponded to both adsorbed water and water from the crystalline hydrates detected with XRD, whereas weight loss on drying and Karl Fischer titration measured only adsorbed water. Overall, lot 0120324/1.1 was determined to be 33% water and 67% vanadyl sulfate.

Elemental analysis to aid in chemical identity confirmation and purity analysis was performed with SEM-EDS, PIXE, and ICP-AES. SEM-EDS signals were present for only vanadium, sulfur, and oxygen in the sample, which is consistent with an identity of vanadyl sulfate without significant impurities. PIXE analysis by Elemental Analysis, Inc. (Lexington, KY) indicated the sample contained 19.5% vanadium and 14.2% sulfur, and no inorganic impurities were detected with concentrations >0.1%. ICP-AES analysis found the sample contained 22.1% vanadium and 14.3% sulfur, which agreed with the theoretical values for vanadium sulfate (20.94% and 13.18%, respectively), and consisted of 33% water.

Analysis using HPLC/CAD (Table A-1, System C) detected only vanadyl and sulfate ions. The volatile content was determined by GC/FID/ECD (Table A-2, System G) using four halogenated and six nonhalogenated standards. No volatiles were detected with GC. The overall purity of lot 0210324/1.1 was determined to be >99%.

Accelerated stability studies were conducted and analyzed using HPLC/CAD (Table A-1, System C). Lot 0210324/1.1 was stored in sealed amber glass vials at refrigerated (5°C), room (25°C), and elevated (60°C) temperatures for 2 weeks and then analyzed for purity relative to a frozen (−20°C) sample. Stability was confirmed for at least 2 weeks when stored sealed in amber glass at temperatures of ≤60°C. Four containers of lot 0210324/1.1 were received and homogenized by mixing all contents in a 1-ft^3^ Patterson-Kelley twin-shell blender for approximately 15 minutes. The bulk chemical was stored at room temperature in white plastic containers. Reanalysis of the bulk chemical using HPLC/CAD (Table A-1, System D) was performed before, during, and after the study by the analytical chemistry laboratory. No significant differences were detected in the purities between the bulk test article and frozen reference standard during reanalysis.

## A.2 Preparation and Analysis of Dose Formulations

### A.2.1 Sodium Metavanadate

The dose formulations for the perinatal (rats) and 3-month exposure (rats and mice) phases of the 3-month studies were prepared monthly at the Battelle study laboratory (West Jefferson, OH) by mixing sodium metavanadate with American Society for Testing and Materials (ASTM) Type I water, adjusted to pH 6 to 8 to give the required concentrations (Table A-3). Dose formulations of sodium metavanadate were prepared at six concentrations of 0, 31.3, 62.5, 125, 250, and 500 mg/L. The formulations were prepared five times for the rat study and three times for the mouse study. All dose formulations were stored at the study laboratory in plastic carboys at refrigerated temperatures (2°C–8°C) and were used within 42 days of preparation.

Stability studies were conducted on 10 mg/L and 30 mg/L sodium metavanadate dose formulations stored in polyethylene bottles protected from light. Formulation stability was measured after 42 days at refrigerated and room temperatures by the study laboratory using HPLC with ultraviolet (UV) detection (Table A-1, System E). Dose formulations were considered stable if the measured concentrations were within 10% of the day 0 concentration. Sodium metavanadate dose formulations were considered stable for up to 42 days when stored sealed at refrigerated or room temperatures and protected from light. A 7-day simulated dosing study was conducted to assess stability of 10 mg/L and 30 mg/L sodium metavanadate dose formulations by storing the formulations in a clear glass bottle with a sipper tube filled to near capacity and hung at room temperature. All sodium metavanadate formulations were considered stable for up to7 days under simulated animal room conditions.

Analysis of preadministration and postadministration (animal room) dose formulations were conducted monthly at the study laboratory according to the same procedure as the formulation stability study (Table A-1, System E). All preadministration dose formulations for sodium metavanadate (Table A-5, Table A-6) were within 10% of the target concentrations. All postadministration samples were within 10% of the target concentrations, except for two animal room samples for the rat study, which were 11.7% and 10.9% below the target concentrations.

### A.2.2 Vanadyl Sulfate

The dose formulations for the perinatal (rats) and 3-month exposure (rats and mice) phases of the 3-month studies were prepared monthly at the Battelle study laboratory (West Jefferson, OH) by mixing vanadyl sulfate with ASTM Type I water, adjusted to pH 3.5 to give the required concentrations (Table A-3). Dose formulations of vanadyl sulfate were prepared at six concentrations of 0, 21.0, 41.9, 83.8, 168, and 335 mg/L (after being corrected for 33% water content). The formulations were prepared five times for the rat study and three times for the mouse study. All dose formulations were stored at the study laboratory in plastic carboys at refrigerated temperatures (2°C–8°C) and were used within 42 days of preparation.

Stability studies were conducted on 10, 30, 50, and 2,000 mg/L vanadyl sulfate dose formulations stored in polyethylene bottles protected from light. Formulation stability was measured after 42 days at refrigerated and room temperatures by the study laboratory using HPLC/UV (Table A-1, Systems E and F). Dose formulations were considered stable if the measured concentrations were within 10% of the day 0 concentration. A small peak corresponding to the retention time of vanadate (V^5+^) was observed in the 50 and 2,000 mg/L vanadyl sulfate formulations; the absolute amount of conversion was similar regardless of the concentration and did not increase with time.^37^ Vanadyl sulfate dose formulations were considered stable for up to 42 days when stored sealed at refrigerated or room temperatures and protected from light. A 7-day simulated dosing study was conducted to assess stability of 10 mg/L and 30 mg/L vanadyl sulfate dose formulations by storing the formulations in a clear glass bottle with a sipper tube filled to near capacity and hung at room temperature. The 10 mg/L and 30 mg/L vanadyl sulfate formulations decreased in concentration by up to 20.7% and 11%, respectively, compared to day 0 concentrations. The appearance of a second chromatographic peak suggests that some oxidation of vanadyl (V^4+^) to vanadate (V^5+^) occurred and was the cause of the reduced test article concentration.

Analysis of preadministration and postadministration (animal room) dose formulations were conducted monthly at the study laboratory according to the same procedure as the formulation stability study (Table A-1, System E). All preadministration dose formulations of vanadyl sulfate (Table A-7, Table A-8) were within 10% of the target concentrations. All postadministration samples were within 10% of target concentrations, except for one animal room sample for the rat study, which was 13.7% below the target concentration.

Table A-1 Liquid Chromatography Systems Used in the Three-month Drinking Water Studies of Sodium Metavanadate and Vanadyl Sulfate

Chromatography | Detection System | Column | Mobile Phase
System A
High-performance liquid chromatography^a^ | Charged aerosol detector | Phenomenex Luna HILIC (150 mm × 4.6 mm, 5 μm particle size) | A: 77% acetonitrile with 0.1% formic acid and 50 mM ammonium formate B: ASTM Type I water with 0.1% formic acid and 50 mM ammonium formate Gradient program: A:B 95:5 to 75:25 in 3 minutes; hold at 75:25 for 4 minutes; 75:25 to 95:5 in 3 minutes; hold at 95:5 for 5 minutes, 1.0 mL/min flow rate
System B
High-performance liquid chromatography^b^ | Charged aerosol detector | Phenomenex Luna HILIC (150 mm × 4.6 mm, 5 μm particle size) | A: Acetonitrile:ASTM Type I water with 0.1% formic acid and 50 mM ammonium formate (77:23) B: ASTM Type I water with 0.1% formic acid and 50 mM ammonium formate Gradient program: A:B 95:5 to 75:25 in 3 minutes; hold at 75:25 for 4 minutes; 75:25 to 95:5 in 3 minutes; hold at 95:5 for 5 minutes, 1 mL/min flow rate
System C
High-performance liquid chromatography^a^ | Charged aerosol detector | Phenomenex Luna HILIC (150 mm × 4.6 mm, 5 μm particle size) | A: Acetonitrile B: Water, 3% formic acid, 50 mM ammonium formate, Gradient program: A:B Isocratic 75:22 for 30 minutes, 0.5 mL/min flow rate
System D
High-performance liquid chromatography^b^ | Charged aerosol detector | Phenomenex Luna HILIC (150 mm × 4.6 mm, 5 μm particle size) | A: Acetonitrile B: Water C: Formic acid and 50 mM ammonium formate Gradient program: A:B:C Isocratic 75:22:3 for 30 minutes, 0.5 mL/min flow rate
System E
High-performance liquid chromatography^c^ | Ultraviolet (282 nm) | Metrohm Metrosep A Sup 5 (50 mm × 4.0 mm, 5 μm particle size) | 13.0–13.1 mM sodium bicarbonate, 4 mM sodium carbonate, 20 mM EDTA in ASTM Type I water, pH 6.6 Isocratic for 10 minutes, 1 mL/min flow rate
System F
High-performance liquid chromatography^b^ | Ultraviolet (282 nm) | Metrohm Metrosep A Sup 5 (50 mm × 4.0 mm, 5 μm particle size) | 12 mM sodium bicarbonate, 4 mM sodium carbonate, 20 mM EDTA in ASTM Type I water, pH 6.6 Isocratic for 10 minutes, 1 mL/min flow rate

ASTM = American Society for Testing and Materials; EDTA = ethylenediaminetetraacetic acid.

^a^ The liquid chromatographs, Waters Alliance Model 2695, were manufactured by Waters (Milford, MA).

^b^ The liquid chromatographs, Agilent 1100, were manufactured by Agilent (Santa Clara, CA).

^c^ The liquid chromatographs, Agilent 1260, were manufactured by Agilent (Santa Clara, CA).

Table A-2 Gas Chromatography System Used in the Three-month Drinking Water Studies of Sodium Metavanadate and Vanadyl Sulfate

Detection System | Column | Carrier Gas | Oven Temperature Program
System G
Flame ionization (260°C) and electron capture detection (260°C)^a^ | Restek Rtx-624 (30 m × 0.53 mm ID, 3 μm film thickness) | Helium at 5 mL/min | 35°C for 14 minutes, then 15°C/min to 40°C, held for 3 minutes, then 15°C/min to 240°C, held for 2 minutes

ID = internal diameter.

^a^ The gas chromatographs, Agilent 6890, were manufactured by Agilent (Santa Clara, CA).

Table A-3 Preparation and Storage of Dose Formulations Administered to Male and Female Rats in the Perinatal and Three-month Drinking Water Studies of Sodium Metavanadate and Vanadyl Sulfate

Sodium Metavanadate | Vanadyl Sulfate
Preparation
The appropriate amount of test article was weighed and transferred into individual Nalgene^®^ containers prefilled with the appropriate volume of vehicle. The weighing container was rinsed at least three times with the vehicle from the mixing container, and the rinse was added to the mixing container. The mixing container contents were blended with an overhead stirrer for ~15 minutes. Approximately 200 mL of formulation was dispensed through the spigot and poured back into the mixing container to ensure that the spigot was clear of any undissolved test article. After mixing, the pH of each formulation batch was measured and adjusted with hydrochloric acid or sodium hydroxide, as necessary. Formulations were prepared monthly throughout the studies.
Vehicle
ASTM Type I water, adjusted to within pH 6 to 8 with 37% hydrochloric acid and/or 10N sodium hydroxide while stirring with a drum stirrer. | ASTM Type I water, adjusted to pH 3.5 ± 0.1 using 37% hydrochloric acid and/or 10N sodium hydroxide.
Chemical Lot Number
8579K (MP Biomedicals, Irvine, CA) | 0210324/1.1 (Noah Technologies Corporation, San Antonio, TX)
Maximum Storage Time
42 days
Storage Conditions
Plastic carboys stored refrigerated at 2°C–8°C.
Analytical Laboratory
Battelle (Columbus, OH)
Study Laboratory
Battelle (West Jefferson, OH)

ASTM = American Society for Testing and Materials.

Table A-4 Preparation and Storage of Dose Formulations Administered to Male and Female Mice in the Three-month Drinking Water Studies of Sodium Metavanadate and Vanadyl Sulfate

Sodium Metavanadate | Vanadyl Sulfate
Preparation
The appropriate amount of test article was weighed and transferred into individual Nalgene carboys, each equipped with a spigot, prefilled with 90% of the final volume of vehicle. The weighing container was rinsed at least three times with the vehicle from the mixing container, and the rinse was added to the mixing container. The mixing container contents were blended with an overhead stirrer for ~15 minutes. After mixing, ~200 mL of formulation was dispensed through the spigot and poured back into the mixing container to ensure that the spigot was clear of any undissolved test article. The formulations were diluted to final volume with vehicle and stirred for ~2 additional minutes. After additional mixing, the pH of each formulation batch was measured and adjusted with hydrochloric acid or sodium hydroxide, as necessary. Formulations were prepared monthly throughout the studies.
Vehicle
ASTM Type I water, adjusted to within pH 6 to 8 with 37% hydrochloric acid and/or 10N sodium hydroxide while stirring with a drum stirrer. | ASTM Type I water, adjusted to pH 3.5 ± 0.1 using 37% hydrochloric acid and/or 10N sodium hydroxide.
Chemical Lot Number
8579K (MP Biomedicals, Irvine, CA) | 0210324/1.1 (Noah Technologies Corporation, San Antonio, TX)
Maximum Storage Time
42 days
Storage Conditions
Plastic carboys stored refrigerated at 2°C–8°C.
Analytical Laboratory
Battelle (Columbus, OH)
Study Laboratory
Battelle (West Jefferson, OH)

ASTM = American Society for Testing and Materials.

Table A-5 Results of Analyses of Dose Formulations Administered to Male and Female Rats in the Perinatal and Three-month Drinking Water Study of Sodium Metavanadate

Date Prepared | Date Analyzed^a^ | Target Concentration (mg/L) | Determined Concentration (mg/L)^b^ | Difference from Target (%)
January 28, 2016 | January 29, 2016 | 0 | BLOQ | NA
January 28, 2016 | January 29, 2016 | 31.3 | 30.9 ± 0.2 | −1.3
January 28, 2016 | January 29, 2016 | 62.5 | 60.2 ± 0.5 | −3.7
January 28, 2016 | January 29, 2016 | 125 | 122 ± 1 | −2.7
January 28, 2016 | January 29, 2016 | 250 | 239 ± 2 | −4.4
January 28, 2016 | January 29, 2016 | 500 | 490 ± 5 | −2.0
February 26, 2016 | March 1, 2016 | 0 | BLOQ | NA
February 26, 2016 | March 1, 2016 | 31.3 | 30.2 ± 0.2 | −3.6
February 26, 2016 | March 1, 2016 | 62.5 | 58.7 ± 0.2 | −6.1
February 26, 2016 | March 1, 2016 | 125 | 121 ± 1 | −3.2
February 26, 2016 | March 1, 2016 | 250 | 240 ± 1 | −4.1
February 26, 2016 | March 1, 2016 | 500 | 487 ± 2 | −2.6
March 28, 2016 | March 28, 2016 | 0 | BLOQ | NA
March 28, 2016 | March 28, 2016 | 31.3 | 30.7 ± 0.2 | −2.0
March 28, 2016 | March 28, 2016 | 62.5 | 58.2 ± 0.2 | −6.9
March 28, 2016 | March 28, 2016 | 125 | 121 ± 0 | −3.2
March 28, 2016 | March 28, 2016 | 250 | 238 ± 1 | −4.7
March 28, 2016 | March 28, 2016 | 500 | 478 ± 3 | −4.5
April 22, 2016 | April 25, 2016 | 0 | BLOQ | NA
April 22, 2016 | April 25, 2016 | 31.3 | 30.0 ± 0.1 | −4.2
April 22, 2016 | April 25, 2016 | 62.5 | 61.5 ± 0.0 | −1.6
April 22, 2016 | April 25, 2016 | 125 | 124 ± 0 | −0.8
April 22, 2016 | April 25, 2016 | 250 | 242 ± 1 | −3.1
April 22, 2016 | April 25, 2016 | 500 | 501 ± 3 | 0.3
May 19, 2016 | May 20, 2016 | 0 | BLOQ | NA
May 19, 2016 | May 20, 2016 | 31.3 | 29.2 ± 0.1 | −6.7
May 19, 2016 | May 20, 2016 | 62.5 | 60.4 ± 0.6 | −3.4
May 19, 2016 | May 20, 2016 | 125 | 119 ± 1 | −4.5
May 19, 2016 | May 20, 2016 | 250 | 239 ± 1 | −4.4
May 19, 2016 | May 20, 2016 | 500 | 477 ± 3 | −4.7
Animal Room Samples
January 28, 2016 (Drinking Water Bottle) | March 16, 2016 | 0 | BLOQ | NA
January 28, 2016 (Drinking Water Bottle) | March 16, 2016 | 31.3 | 29.6 ± 0.2 | −5.5
January 28, 2016 (Drinking Water Bottle) | March 16, 2016 | 62.5 | 55.2 ± 0.2 | −11.7
January 28, 2016 (Drinking Water Bottle) | March 16, 2016 | 125 | 111 ± 2 | −10.9
January 28, 2016 (Drinking Water Bottle) | March 16, 2016 | 250 | 224 ± 1 | −10.4
January 28, 2016 (Drinking Water Bottle) | March 16, 2016 | 500 | 478 ± 0 | −4.4
January 28, 2016 (Carboy) | March 16, 2016 | 0 | BLOQ | NA
January 28, 2016 (Carboy) | March 16, 2016 | 31.3 | 30.8 ± 0.1 | −1.7
January 28, 2016 (Carboy) | March 16, 2016 | 62.5 | 60.3 ± 0.3 | −3.6
January 28, 2016 (Carboy) | March 16, 2016 | 125 | 119 ± 1 | −4.5
January 28, 2016 (Carboy) | March 16, 2016 | 250 | 235 ± 1 | −6.0
January 28, 2016 (Carboy) | March 16, 2016 | 500 | 485 ± 0 | −3.0
February 26, 2016 (Drinking Water Bottle) | April 12, 2016 | 0 | BLOQ | NA
February 26, 2016 (Drinking Water Bottle) | April 12, 2016 | 31.3 | 30.6 ± 0.2 | −2.1
February 26, 2016 (Drinking Water Bottle) | April 12, 2016 | 62.5 | 59.0 ± 0.6 | −5.5
February 26, 2016 (Drinking Water Bottle) | April 12, 2016 | 125 | 119 ± 1 | −5.1
February 26, 2016 (Drinking Water Bottle) | April 12, 2016 | 250 | 230 ± 1 | −8.0
February 26, 2016 (Drinking Water Bottle) | April 12, 2016 | 500 | 483 ± 3 | −3.3
February 26, 2016 (Carboy) | April 12, 2016 | 0 | BLOQ | NA
February 26, 2016 (Carboy) | April 12, 2016 | 31.3 | 30.4 ± 0.4 | −2.9
February 26, 2016 (Carboy) | April 12, 2016 | 62.5 | 58.9 ± 0.1 | −5.8
February 26, 2016 (Carboy) | April 12, 2016 | 125 | 121 ± 1 | −2.9
February 26, 2016 (Carboy) | April 12, 2016 | 250 | 237 ± 2 | −5.2
February 26, 2016 (Carboy) | April 12, 2016 | 500 | 489 ± 4 | −2.3
March 28, 2016 (Drinking Water Bottle) | May 10, 2016 | 0 | BLOQ | NA
March 28, 2016 (Drinking Water Bottle) | May 10, 2016 | 31.3 | 31.3 ± 0.1 | 0.1
March 28, 2016 (Drinking Water Bottle) | May 10, 2016 | 62.5 | 60.9 ± 0.1 | −2.6
March 28, 2016 (Drinking Water Bottle) | May 10, 2016 | 125 | 124 ± 2 | −0.5
March 28, 2016 (Drinking Water Bottle) | May 10, 2016 | 250 | 244 ± 1 | −2.5
March 28, 2016 (Drinking Water Bottle) | May 10, 2016 | 500 | 483 ± 4 | −3.5
March 28, 2016 (Carboy) | May 10, 2016 | 0 | BLOQ | NA
March 28, 2016 (Carboy) | May 10, 2016 | 31.3 | 31.4 ± 0.1 | 0.2
March 28, 2016 (Carboy) | May 10, 2016 | 62.5 | 60.7 ± 0.4 | −2.9
March 28, 2016 (Carboy) | May 10, 2016 | 125 | 125 ± 2 | −0.3
March 28, 2016 (Carboy) | May 10, 2016 | 250 | 236 ± 1 | −5.7
March 28, 2016 (Carboy) | May 10, 2016 | 500 | 484 ± 4 | −3.1
April 22, 2016 (Drinking Water Bottle) | June 3, 2016 | 0 | BLOQ | NA
April 22, 2016 (Drinking Water Bottle) | June 3, 2016 | 31.3 | 31.1 ± 0.1 | −0.5
April 22, 2016 (Drinking Water Bottle) | June 3, 2016 | 62.5 | 62.4 ± 0.4 | −0.2
April 22, 2016 (Drinking Water Bottle) | June 3, 2016 | 125 | 123 ± 1 | −1.6
April 22, 2016 (Drinking Water Bottle) | June 3, 2016 | 250 | 243 ± 3 | −2.7
April 22, 2016 (Drinking Water Bottle) | June 3, 2016 | 500 | 509 ± 4 | 1.7
April 22, 2016 (Carboy) | June 3, 2016 | 0 | BLOQ | NA
April 22, 2016 (Carboy) | June 3, 2016 | 31.3 | 30.8 ± 0.1 | −1.7
April 22, 2016 (Carboy) | June 3, 2016 | 62.5 | 62.5 ± 0.5 | 0.0
April 22, 2016 (Carboy) | June 3, 2016 | 125 | 127 ± 1 | 1.9
April 22, 2016 (Carboy) | June 3, 2016 | 250 | 242 ± 2 | −3.2
April 22, 2016 (Carboy) | June 3, 2016 | 500 | 518 ± 16 | 3.5
May 19, 2016 (Drinking Water Bottle) | July 1, 2016 | 0 | BLOQ | NA
May 19, 2016 (Drinking Water Bottle) | July 1, 2016 | 31.3 | 32.4 ± 0.2 | 3.6
May 19, 2016 (Drinking Water Bottle) | July 1, 2016 | 62.5 | 57.9 ± 0.1 | −7.3
May 19, 2016 (Drinking Water Bottle) | July 1, 2016 | 125 | 122 ± 0 | −2.4
May 19, 2016 (Drinking Water Bottle) | July 1, 2016 | 250 | 256 ± 3 | 2.5
May 19, 2016 (Drinking Water Bottle) | July 1, 2016 | 500 | 500 ± 5 | 0.1
May 19, 2016 (Carboy) | July 1, 2016 | 0 | BLOQ | NA
May 19, 2016 (Carboy) | July 1, 2016 | 31.3 | 31.4 ± 0.7 | 0.4
May 19, 2016 (Carboy) | July 1, 2016 | 62.5 | 61.7 ± 0.7 | −1.3
May 19, 2016 (Carboy) | July 1, 2016 | 125 | 126 ± 6 | 0.5
May 19, 2016 (Carboy) | July 1, 2016 | 250 | 240 ± 4 | −4.0
May 19, 2016 (Carboy) | July 1, 2016 | 500 | 491 ± 3 | −1.7

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Date first chromatograms were acquired.

^b^ Data are presented as mean ± standard deviation of triplicate analysis.

Table A-6 Results of Analyses of Dose Formulations Administered to Male and Female Mice in the Three-month Drinking Water Study of Sodium Metavanadate

Date Prepared | Date Analyzed^a^ | Target Concentration (mg/L) | Determined Concentration (mg/L)^b^ | Difference from Target (%)
January 13, 2016 | January 14, 2016 | 0 | BLOQ | NA
January 13, 2016 | January 14, 2016 | 31.3 | 31.0 ± 0.3 | −1.0
January 13, 2016 | January 14, 2016 | 62.5 | 62.1 ± 0.2 | −0.6
January 13, 2016 | January 14, 2016 | 125 | 124 ± 1 | −0.5
January 13, 2016 | January 14, 2016 | 250 | 236 ± 2 | −5.6
January 13, 2016 | January 14, 2016 | 500 | 481 ± 4 | −3.8
February 11, 2016 | February 12, 2016 | 0 | BLOQ | NA
February 11, 2016 | February 12, 2016 | 31.3 | 29.7 ± 0.6 | −5.2
February 11, 2016 | February 12, 2016 | 62.5 | 60.5 ± 1.6 | −3.1
February 11, 2016 | February 12, 2016 | 125 | 125 ± 1 | 0.3
February 11, 2016 | February 12, 2016 | 250 | 249 ± 1 | −0.5
February 11, 2016 | February 12, 2016 | 500 | 498 ± 3 | −0.5
March 15, 2016 | March 15, 2016 | 0 | BLOQ | NA
March 15, 2016 | March 15, 2016 | 31.3 | 31.2 ± 0.1 | −0.3
March 15, 2016 | March 15, 2016 | 62.5 | 62.7 ± 0.4 | 0.3
March 15, 2016 | March 15, 2016 | 125 | 124 ± 1 | −0.8
March 15, 2016 | March 15, 2016 | 250 | 248 ± 1 | −0.7
March 15, 2016 | March 15, 2016 | 500 | 498 ± 3 | −0.5
Animal Room Samples
January 13, 2016 (Drinking Water Bottle) | February 24, 2016 | 0 | BLOQ | NA
January 13, 2016 (Drinking Water Bottle) | February 24, 2016 | 31.3 | 31.8 ± 0.2 | 1.5
January 13, 2016 (Drinking Water Bottle) | February 24, 2016 | 62.5 | 62.9 ± 0.1 | 0.6
January 13, 2016 (Drinking Water Bottle) | February 24, 2016 | 125 | 125 ± 1 | −0.3
January 13, 2016 (Drinking Water Bottle) | February 24, 2016 | 250 | 251 ± 2 | 0.4
January 13, 2016 (Drinking Water Bottle) | February 24, 2016 | 500 | 506 ± 4 | 1.2
January 13, 2016 (Carboy) | February 24, 2016 | 0 | BLOQ | NA
January 13, 2016 (Carboy) | February 24, 2016 | 31.3 | 31.4 ± 0.3 | 0.4
January 13, 2016 (Carboy) | February 24, 2016 | 62.5 | 62.1 ± 0.7 | −0.6
January 13, 2016 (Carboy) | February 24, 2016 | 125 | 122 ± 1 | −2.1
January 13, 2016 (Carboy) | February 24, 2016 | 250 | 248 ± 2 | −0.8
January 13, 2016 (Carboy) | February 24, 2016 | 500 | 498 ± 3 | −0.5
February 11, 2016 (Drinking Water Bottle) | March 23, 2016 | 0 | BLOQ | NA
February 11, 2016 (Drinking Water Bottle) | March 23, 2016 | 31.3 | 31.4 ± 0.2 | 0.2
February 11, 2016 (Drinking Water Bottle) | March 23, 2016 | 62.5 | 63.4 ± 0.5 | 1.5
February 11, 2016 (Drinking Water Bottle) | March 23, 2016 | 125 | 124 ± 1 | −1.1
February 11, 2016 (Drinking Water Bottle) | March 23, 2016 | 250 | 245 ± 6 | −2.1
February 11, 2016 (Drinking Water Bottle) | March 23, 2016 | 500 | 499 ± 1 | −0.1
February 11, 2016 (Carboy) | March 23, 2016 | 0 | BLOQ | NA
February 11, 2016 (Carboy) | March 23, 2016 | 31.3 | 31.2 ± 0.2 | −0.3
February 11, 2016 (Carboy) | March 23, 2016 | 62.5 | 61.7 ± 0.2 | −1.3
February 11, 2016 (Carboy) | March 23, 2016 | 125 | 124 ± 1 | −0.5
February 11, 2016 (Carboy) | March 23, 2016 | 250 | 248 ± 2 | −0.8
February 11, 2016 (Carboy) | March 23, 2016 | 500 | 501 ± 3 | 0.3
March 15, 2016 (Drinking Water Bottle) | April 27, 2016 | 0 | BLOQ | NA
March 15, 2016 (Drinking Water Bottle) | April 27, 2016 | 31.3 | 31.9 ± 0.3 | 1.9
March 15, 2016 (Drinking Water Bottle) | April 27, 2016 | 62.5 | 63.7 ± 0.2 | 1.9
March 15, 2016 (Drinking Water Bottle) | April 27, 2016 | 125 | 123 ± 1 | −1.3
March 15, 2016 (Drinking Water Bottle) | April 27, 2016 | 250 | 244 ± 1 | −2.4
March 15, 2016 (Drinking Water Bottle) | April 27, 2016 | 500 | 480 ± 12 | −4.1
March 15, 2016 (Carboy) | April 27, 2016 | 0 | BLOQ | NA
March 15, 2016 (Carboy) | April 27, 2016 | 31.3 | 31.4 ± 0.2 | 0.4
March 15, 2016 (Carboy) | April 27, 2016 | 62.5 | 61.8 ± 0.3 | −1.2
March 15, 2016 (Carboy) | April 27, 2016 | 125 | 123 ± 1 | −1.9
March 15, 2016 (Carboy) | April 27, 2016 | 250 | 245 ± 4 | −1.9
March 15, 2016 (Carboy) | April 27, 2016 | 500 | 479 ± 1 | −4.3

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Date first chromatograms were acquired.

^b^ Data are presented as mean ± standard deviation of triplicate analysis.

Table A-7 Results of Analyses of Dose Formulations Administered to Male and Female Rats in the Perinatal and Three-month Drinking Water Study of Vanadyl Sulfate

Date Prepared | Date Analyzed^a^ | Target Concentration (mg/L) | Determined Concentration (mg/L)^b^ | Difference from Target (%)
April 15, 2016 | April 18, 2016 | 0 | BLOQ | NA
April 15, 2016 | April 18, 2016 | 21.0 | 20.1 ± 0.2 | −4.4
April 15, 2016 | April 18, 2016 | 41.9 | 39.5 ± 0.7 | −5.6
April 15, 2016 | April 18, 2016 | 83.8 | 82.8 ± 1.3 | −1.2
April 15, 2016 | April 18, 2016 | 168 | 159 ± 4 | −5.2
April 15, 2016 | April 18, 2016 | 335 | 319 ± 5 | −4.7
May 10, 2016 | May 12, 2016 | 0 | BLOQ | NA
May 10, 2016 | May 12, 2016 | 21.0 | 21.2 ± 0.3 | 0.8
May 10, 2016 | May 12, 2016 | 41.9 | 41.7 ± 0.6 | −0.6
May 10, 2016 | May 12, 2016 | 83.8 | 83.8 ± 1.9 | 0.0
May 10, 2016 | May 12, 2016 | 168 | 170 ± 2 | 1.4
May 10, 2016 | May 12, 2016 | 335 | 339 ± 6 | 1.1
June 13, 2016 | June 15, 2016 | 0 | BLOQ | NA
June 13, 2016 | June 15, 2016 | 21.0 | 20.7 ± 0.0 | −1.4
June 13, 2016 | June 15, 2016 | 41.9 | 39.2 ± 0.2 | −6.4
June 13, 2016 | June 15, 2016 | 83.8 | 78.7 ± 0.6 | −6.1
June 13, 2016 | June 15, 2016 | 168 | 158 ± 1 | −5.8
June 13, 2016 | June 15, 2016 | 335 | 321 ± 2 | −4.2
July 11, 2016 | July 19, 2016 | 0 | BLOQ | NA
July 11, 2016 | July 19, 2016 | 21.0 | 21.7 ± 0.9 | 3.2
July 11, 2016 | July 19, 2016 | 41.9 | 40.8 ± 0.3 | −2.5
July 11, 2016 | July 19, 2016 | 83.8 | 82.5 ± 0.5 | −1.6
July 11, 2016 | July 19, 2016 | 168 | 168 ± 4 | 0.4
July 11, 2016 | July 19, 2016 | 335 | 344 ± 1 | 2.8
August 3, 2016 | August 5, 2016 | 0 | BLOQ | NA
August 3, 2016 | August 5, 2016 | 21.0 | 20.1 ± 0.2 | −4.4
August 3, 2016 | August 5, 2016 | 41.9 | 40.7 ± 0.2 | −2.8
August 3, 2016 | August 5, 2016 | 83.8 | 82.7 ± 0.3 | −1.4
August 3, 2016 | August 5, 2016 | 168 | 164 ± 1 | −2.2
August 3, 2016 | August 5, 2016 | 335 | 329 ± 1 | −1.7
Animal Room Samples
April 15, 2016 (Drinking Water Bottle) | May 25, 2016 | 0 | BLOQ | NA
April 15, 2016 (Drinking Water Bottle) | May 25, 2016 | 21.0 | 20.7 ± 0.1 | −1.6
April 15, 2016 (Drinking Water Bottle) | May 25, 2016 | 41.9 | 40.6 ± 0.5 | −3.1
April 15, 2016 (Drinking Water Bottle) | May 25, 2016 | 83.8 | 83.2 ± 0.6 | −0.8
April 15, 2016 (Drinking Water Bottle) | May 25, 2016 | 168 | 165 ± 1 | −1.6
April 15, 2016 (Drinking Water Bottle) | May 25, 2016 | 335 | 334 ± 1 | −0.4
April 15, 2016 (Carboy) | May 25, 2016 | 0 | BLOQ | NA
April 15, 2016 (Carboy) | May 25, 2016 | 21.0 | 20.8 ± 0.1 | −1.0
April 15, 2016 (Carboy) | May 25, 2016 | 41.9 | 43.0 ± 2.0 | 2.7
April 15, 2016 (Carboy) | May 25, 2016 | 83.8 | 85.5 ± 2.6 | 2.0
April 15, 2016 (Carboy) | May 25, 2016 | 168 | 169 ± 1 | 0.4
April 15, 2016 (Carboy) | May 25, 2016 | 335 | 335 ± 6 | 0.1
May 10, 2016 (Drinking Water Bottle) | June 23, 2016 | 0 | BLOQ | NA
May 10, 2016 (Drinking Water Bottle) | June 23, 2016 | 21.0 | 21.1 ± 0.1 | 0.3
May 10, 2016 (Drinking Water Bottle) | June 23, 2016 | 41.9 | 42.3 ± 0.3 | 0.9
May 10, 2016 (Drinking Water Bottle) | June 23, 2016 | 83.8 | 84.0 ± 0.5 | 0.2
May 10, 2016 (Drinking Water Bottle) | June 23, 2016 | 168 | 168 ± 0 | 0.0
May 10, 2016 (Drinking Water Bottle) | June 23, 2016 | 335 | 339 ± 4 | 1.3
May 10, 2016 (Carboy) | June 23, 2016 | 0 | BLOQ | NA
May 10, 2016 (Carboy) | June 23, 2016 | 21.0 | 21.3 ± 0.1 | 1.3
May 10, 2016 (Carboy) | June 23, 2016 | 41.9 | 42.9 ± 0.1 | 2.3
May 10, 2016 (Carboy) | June 23, 2016 | 83.8 | 79.3 ± 6.8 | −5.3
May 10, 2016 (Carboy) | June 23, 2016 | 168 | 174 ± 0 | 3.6
May 10, 2016 (Carboy) | June 23, 2016 | 335 | 344 ± 4 | 2.6
June 13, 2016 (Drinking Water Bottle) | July 26, 2016 | 0 | BLOQ | NA
June 13, 2016 (Drinking Water Bottle) | July 26, 2016 | 21.0 | 20.4 ± 0.3 | −2.8
June 13, 2016 (Drinking Water Bottle) | July 26, 2016 | 41.9 | 37.9 ± 0.1 | −9.5
June 13, 2016 (Drinking Water Bottle) | July 26, 2016 | 83.8 | 76.5 ± 0.5 | −8.7
June 13, 2016 (Drinking Water Bottle) | July 26, 2016 | 168 | 145 ± 1 | −13.7
June 13, 2016 (Drinking Water Bottle) | July 26, 2016 | 335 | 317 ± 3 | −5.5
June 13, 2016 (Carboy) | July 26, 2016 | 0 | BLOQ | NA
June 13, 2016 (Carboy) | July 26, 2016 | 21.0 | 20.5 ± 0.3 | −2.5
June 13, 2016 (Carboy) | July 26, 2016 | 41.9 | 38.4 ± 0.1 | −8.3
June 13, 2016 (Carboy) | July 26, 2016 | 83.8 | 76.2 ± 0.3 | −9.1
June 13, 2016 (Carboy) | July 26, 2016 | 168 | 154 ± 2 | −8.1
June 13, 2016 (Carboy) | July 26, 2016 | 335 | 314 ± 6 | −6.4
July 11, 2016 (Drinking Water Bottle) | August 23, 2016 | 0 | BLOQ | NA
July 11, 2016 (Drinking Water Bottle) | August 23, 2016 | 21.0 | 21.4 ± 0.1 | 1.9
July 11, 2016 (Drinking Water Bottle) | August 23, 2016 | 41.9 | 41.2 ± 0.2 | −1.6
July 11, 2016 (Drinking Water Bottle) | August 23, 2016 | 83.8 | 81.5 ± 0.9 | −2.7
July 11, 2016 (Drinking Water Bottle) | August 23, 2016 | 168 | 159 ± 1 | −5.2
July 11, 2016 (Drinking Water Bottle) | August 23, 2016 | 335 | 318 ± 0 | −5.1
July 11, 2016 (Carboy) | August 23, 2016 | 0 | BLOQ | NA
July 11, 2016 (Carboy) | August 23, 2016 | 21.0 | 21.3 ± 0.1 | 1.6
July 11, 2016 (Carboy) | August 23, 2016 | 41.9 | 39.9 ± 0.1 | −4.8
July 11, 2016 (Carboy) | August 23, 2016 | 83.8 | 82.0 ± 0.5 | −2.1
July 11, 2016 (Carboy) | August 23, 2016 | 168 | 168 ± 3 | 0.2
July 11, 2016 (Carboy) | August 23, 2016 | 335 | 340 ± 5 | 1.5
August 3, 2016 (Drinking Water Bottle) | September 16, 2016 | 0 | BLOQ | NA
August 3, 2016 (Drinking Water Bottle) | September 16, 2016 | 21.0 | 19.6 ± 0.1 | −6.7
August 3, 2016 (Drinking Water Bottle) | September 16, 2016 | 41.9 | 39.7 ± 0.5 | −5.2
August 3, 2016 (Drinking Water Bottle) | September 16, 2016 | 83.8 | 79.7 ± 1.0 | −4.9
August 3, 2016 (Drinking Water Bottle) | September 16, 2016 | 168 | 160 ± 2 | −5.0
August 3, 2016 (Drinking Water Bottle) | September 16, 2016 | 335 | 321 ± 2 | −4.2
August 3, 2016 (Carboy) | September 16, 2016 | 0 | BLOQ | NA
August 3, 2016 (Carboy) | September 16, 2016 | 21.0 | 19.7 ± 0.2 | −6.0
August 3, 2016 (Carboy) | September 16, 2016 | 41.9 | 40.4 ± 0.1 | −3.5
August 3, 2016 (Carboy) | September 16, 2016 | 83.8 | 81.2 ± 0.8 | −3.1
August 3, 2016 (Carboy) | September 16, 2016 | 168 | 161 ± 3 | −4.2
August 3, 2016 (Carboy) | September 16, 2016 | 335 | 322 ± 9 | −3.9

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Date first chromatograms were acquired.

^b^ Data are presented as mean ± standard deviation of triplicate analysis.

Table A-8 Results of Analyses of Dose Formulations Administered to Male and Female Mice in the Three-month Drinking Water Study of Vanadyl Sulfate

Date Prepared | Date Analyzed^a^ | Target Concentration (mg/L) | Determined Concentration (mg/L)^b^ | Difference from Target (%)
April 4, 2016 | April 5, 2016 | 0 | BLOQ | NA
April 4, 2016 | April 5, 2016 | 21.0 | 21.2 ± 0.1 | 1.1
April 4, 2016 | April 5, 2016 | 41.9 | 41.5 ± 0.8 | −0.9
April 4, 2016 | April 5, 2016 | 83.8 | 83.0 ± 2.2 | −0.9
April 4, 2016 | April 5, 2016 | 168 | 168 ± 3 | 0.2
April 4, 2016 | April 5, 2016 | 335 | 323 ± 12 | −3.5
April 28, 2016 | April 28, 2016 | 0 | BLOQ | NA
April 28, 2016 | April 28, 2016 | 21.0 | 21.1 ± 0.4 | 0.6
April 28, 2016 | April 28, 2016 | 41.9 | 42.4 ± 0.8 | 1.2
April 28, 2016 | April 28, 2016 | 83.8 | 85.5 ± 0.9 | 2.0
April 28, 2016 | April 28, 2016 | 168 | 172 ± 5 | 2.2
April 28, 2016 | April 28, 2016 | 335 | 344 ± 1 | 2.8
May 31, 2016 | June 1, 2016 | 0 | BLOQ | NA
May 31, 2016 | June 1, 2016 | 21.0 | 21.1 ± 0.3 | 0.6
May 31, 2016 | June 1, 2016 | 41.9 | 42.4 ± 0.4 | 1.1
May 31, 2016 | June 1, 2016 | 83.8 | 84.3 ± 1.2 | 0.6
May 31, 2016 | June 1, 2016 | 168 | 162 ± 1 | −3.4
May 31, 2016 | June 1, 2016 | 335 | 334 ± 6 | −0.2
Animal Room Samples
April 4, 2016 (Drinking Water Bottle) | May 11, 2016 | 0 | BLOQ | NA
April 4, 2016 (Drinking Water Bottle) | May 11, 2016 | 21.0 | 20.3 ± 0.3 | −3.3
April 4, 2016 (Drinking Water Bottle) | May 11, 2016 | 41.9 | 39.9 ± 0.6 | −4.8
April 4, 2016 (Drinking Water Bottle) | May 11, 2016 | 83.8 | 80.7 ± 0.8 | −3.7
April 4, 2016 (Drinking Water Bottle) | May 11, 2016 | 168 | 163 ± 4 | −3.2
April 4, 2016 (Drinking Water Bottle) | May 11, 2016 | 335 | 312 ± 4 | −6.9
April 4, 2016 (Carboy) | May 11, 2016 | 0 | BLOQ | NA
April 4, 2016 (Carboy) | May 11, 2016 | 21.0 | 20.8 ± 0.1 | −0.8
April 4, 2016 (Carboy) | May 11, 2016 | 41.9 | 42.0 ± 0.8 | 0.2
April 4, 2016 (Carboy) | May 11, 2016 | 83.8 | 82.7 ± 1.9 | −1.4
April 4, 2016 (Carboy) | May 11, 2016 | 168 | 162 ± 3 | −3.6
April 4, 2016 (Carboy) | May 11, 2016 | 335 | 329 ± 10 | −1.9
April 28, 2016 (Drinking Water Bottle) | June 8, 2016 | 0 | BLOQ | NA
April 28, 2016 (Drinking Water Bottle) | June 8, 2016 | 21.0 | 22.2 ± 0.2 | 5.6
April 28, 2016 (Drinking Water Bottle) | June 8, 2016 | 41.9 | 44.2 ± 0.8 | 5.5
April 28, 2016 (Drinking Water Bottle) | June 8, 2016 | 83.8 | 87.7 ± 0.8 | 4.6
April 28, 2016 (Drinking Water Bottle) | June 8, 2016 | 168 | 181 ± 7 | 7.5
April 28, 2016 (Drinking Water Bottle) | June 8, 2016 | 335 | 340 ± 3 | 1.6
April 28, 2016 (Carboy) | June 8, 2016 | 0 | BLOQ | NA
April 28, 2016 (Carboy) | June 8, 2016 | 21.0 | 22.5 ± 0.5 | 7.3
April 28, 2016 (Carboy) | June 8, 2016 | 41.9 | 43.9 ± 0.1 | 4.8
April 28, 2016 (Carboy) | June 8, 2016 | 83.8 | 88.3 ± 1.2 | 5.4
April 28, 2016 (Carboy) | June 8, 2016 | 168 | 178 ± 4 | 5.7
April 28, 2016 (Carboy) | June 8, 2016 | 335 | 355 ± 8 | 5.9
May 31, 2016 (Drinking Water Bottle) | July 15, 2016 | 0 | BLOQ | NA
May 31, 2016 (Drinking Water Bottle) | July 15, 2016 | 21.0 | 19.6 ± 0.1 | −6.8
May 31, 2016 (Drinking Water Bottle) | July 15, 2016 | 41.9 | 41.5 ± 0.6 | −0.9
May 31, 2016 (Drinking Water Bottle) | July 15, 2016 | 83.8 | 82.8 ± 0.3 | −1.2
May 31, 2016 (Drinking Water Bottle) | July 15, 2016 | 168 | 163 ± 3 | −2.8
May 31, 2016 (Drinking Water Bottle) | July 15, 2016 | 335 | 339 ± 4 | 1.3
May 31, 2016 (Carboy) | July 15, 2016 | 0 | BLOQ | NA
May 31, 2016 (Carboy) | July 15, 2016 | 21.0 | 20.4 ± 0.3 | −2.9
May 31, 2016 (Carboy) | July 15, 2016 | 41.9 | 42.2 ± 0.2 | 0.7
May 31, 2016 (Carboy) | July 15, 2016 | 83.8 | 83.7 ± 0.3 | −0.2
May 31, 2016 (Carboy) | July 15, 2016 | 168 | 169 ± 6 | 0.4
May 31, 2016 (Carboy) | July 15, 2016 | 335 | 338 ± 5 | 0.8

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Date first chromatograms were acquired.

^b^ Data are presented as mean ± standard deviation of triplicate analysis.

Figure A-1

Infrared Absorption Spectrum of Sodium Metavanadate

Figure A-2

Indexed X-ray Diffraction Pattern for Sodium Metavanadate and Metamunirite

Indexed X-ray diffraction pattern for the test article sodium metavanadate (black) overlaid with reference pattern (red) of metamunirite (NaVO_3_). Peaks marked with a 1 indicate a match between the sample and metamunirite.

Figure A-3

Infrared Absorption Spectrum of Vanadyl Sulfate

Figure A-4

Indexed X-ray Diffraction Pattern for Vanadyl Sulfate and Minasragrite

Indexed X-ray diffraction pattern for the test article vanadyl sulfate (black) overlaid with the reference pattern (red) of minasragrite ((VO)(SO_4_)^·5H^_^2^_^O^). Peaks marked with a 1 indicate a match between the sample and minasragrite. The x-axis has been split into two ranges for clarity.

Figure A-5

Indexed X-ray Diffraction Pattern for Vanadyl Sulfate and Bobjonesite

Indexed X-ray diffraction pattern for the test article vanadyl sulfate (black) overlaid with reference pattern (blue) of bobjonesite ((VO)(SO_4_)^·3H2O^). Peaks marked with a 2 indicate a match between the sample and bobjonesite. The x-axis has been split into two ranges for clarity.