# Peer Review

The National Toxicology Program (NTP) conducted a peer review of the draft NTP Technical Report on the Toxicity Studies of Usnea Lichens Containing (+/−)-Usnic Acid (CASRN 125-46-2) Administered in Feed to F344/N Nctr Rats and B6C3F1/Nctr Mice by letter in November 2021 by the experts listed below. Reviewer selection and document review followed established NTP practices. The reviewers were charged to:

1. Peer review the draft NTP Technical Report on the Toxicity Studies of Usnea Lichens Containing (+/−)-Usnic Acid.
2. Comment on NTP’s interpretations of the data.

NTP carefully considered reviewer comments in finalizing this report.

## Peer Reviewers

- Howard Perry Glauert, Ph.D.
  Professor, Director of Graduate Studies, Pharmacology and Nutritional Sciences
  University of Kentucky College of Medicine
  Lexington, Kentucky, USA
- JoEllyn M. McMillan, Ph.D.
  Associate Professor
  University of Nebraska
  Omaha, Nebraska, USA