# Collaborators

- National Center for Toxicological Research, U.S. Food and Drug Administration, Jefferson, Arkansas, USA
  Conducted study, evaluated and interpreted results and pathology findings, reported findings, and prepared the study report
  J.E.A. Leakey, Ph.D., Study Scientist
  S. Lewis, Ph.D., Co-Investigator (Retired)
  A.A. Ali, Ph.D.
  W.T. Allaben, Ph.D. (Retired)
  A.R. Babb, B.S.
  P.C. Howard, Ph.D. (Retired)
- Conducted microbiology surveillance and diagnostics
  R.M. Colvert, B.S. (Retired)
  M.A. Holland, B.S. (Retired)
  S.J. Johnson, M.S.
  D.D. Paine, B.S. (Retired)
  L.M. Sims, B.S.
  R.S. Steele, B.S.
  C.V. Summage-West, B.S.
  R.D. Wagner, Ph.D.
- Conducted dose certifications and chemical analyses
  C.R. Cozart, B.S. (Retired)
  J. Deck, B.S. (Retired)
  R.L. Evans, B.S. (Retired)
  J.P. Freeman, Ph.D. (Retired)
  T.M. Heinze, M.S. (Retired)
  P.H. Siitonen, B.S. (Retired)
- Conducted statistical analyses
  R.P. Felton, M.S.
  B.E. Juliar, M.A., M.S. (Retired)
- Conducted quality assurance audits
  J.M. Fowler, B.S.
  R.D. Smith, B.S.
- Prepared technical report
  S.C. Matson, Ph.D., Project Leader (Retired)
  R.L. Adams, B.A.
  S.L. King, M.A.
  R.L. Stingley, Ph.D.
- Division of Translational Toxicology, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Reviewed and evaluated the technical report, interpreted results and pathology findings
  C.R. Blystone, Ph.D.
  M.F. Cesta, D.V.M., Ph.D.
  H.C. Cunny, Ph.D.
  G.K. Roberts, Ph.D.
  K.A. Shipkowski, Ph.D.
  K.R. Shockley, Ph.D.
  V.L. Sutherland, Ph.D.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Toxicologic Pathology Associates, Jefferson, Arkansas, USA
  Evaluated pathology findings
  G.R. Olson, D.V.M., Ph.D., Study Pathologist (Retired)
  A.R. Warbritton
  L.P. Wiley, B.S.
- Southern Research, Birmingham, Alabama, USA
  Evaluated female reproductive toxicology
  E. Mylchreest, Ph.D.
- RTI International, Research Triangle Park, North Carolina, USA
  Evaluated male reproductive toxicology
  C.S. Sloan, M.S.
  R.W. Tyl, Ph.D.