# References

1 Crawford SD. Lichens used in traditional medicine. In Lichen Secondary Metabolites: Bioactive Properties and Pharmaceutical Potential. Cham, Switzerland: Springer International Publishing; 2015. Lichens used in traditional medicine; p. 27–80. 10.1007/978-3-319-13374-4_2
2 Ingólfsdóttir K. Usnic acid. Phytochemistry. 2002; 61(7):729–736. 10.1016/S0031-9422(02)00383-7 12453567
3 Brodo IM, Sharnoff SD, Sharnoff S. Lichens of North America. New Haven, CT: Yale University Press; 2001.
4 Gao H, Zou J, Li J, Zhao H. Studies in Natural Products Chemistry. Amsterdam, Netherlands: Elsevier; 2016. Endolichenic fungi: A potential treasure trove for discovery of special structures and bioactive compounds; p. 347–397.
5 Huneck S. The significance of lichens and their metabolites. Naturwissenschaften. 1999; 86(12):559–570. 10.1007/s001140050676 10643590
6 Lücking R, Rivas Plata E, Chaves JL, Umaña L, Sipman HJM. How many tropical lichens are there ... really? Bibl Lichenol. 2009;100:399–418.
7 Thell A, Crespo A, Divakar PK, Kärnefelt I, Leavitt SD, Lumbsch HT, Seaward MRD. A review of the lichen family Parmeliaceae – History, phylogeny and current taxonomy. Nord J Bot. 2012; 30(6):641–664. 10.1111/j.1756-1051.2012.00008.x
8 Hsu HY. Oriental materia medica: A concise guide. Long Beach, CA: Oriental Healing Arts Institute; 1986.
9 Lin CK. The lichen genus Usnea at Meifeng, central Taiwan. Coll Res. 2007;20:1–7.
10 Ohmura Y, Skirina I, Skirin F. Contribution to the knowledge of the genus Usnea (parmeliaceae, ascomycota) in southern Far East Russia. Bull Natl Mus Nat Sci. Ser B. 2017; 43(1):1–10.
11 Boustie J, Grube M. Lichens - A promising source of bioactive secondary metabolites. Plant Genet Resour. 2005; 3(2):273–287. 10.1079/PGR200572
12 Huneck S, Yoshimura I. Identification of lichen substances. Berlin, Germany: Springer-Verlag; 1996. 10.1007/978-3-642-85243-5
13 Crockett M, Kageyama S, Homen D, Lewis C, Osborn J, Sander L. Antimicrobial properties of four Pacific Northwest lichens. Corvallis, OR: Oregon State University Press; 2003.
14 Prateeksha, Paliya BS, Bajpai R, Jadaun V, Kumar J, Kumar S, Upreti DK, Singh BR, Nayaka S, Joshi Y et al. The genus Usnea: A potent phytomedicine with multifarious ethnobotany, phytochemistry and pharmacology. RSC Advances. 2016; 6(26):21672-21696.
15 Halonen P, Clerc P, Goward T, Brodo IM, Wulff K. Synopsis of the genus Usnea (Lichenized Ascomycetes) in British Columbia, Canada. Bryologist. 1998; 101(1):36–60. 10.1639/0007-2745(1998)101[36:SOTGUL]2.0.CO;2
16 Salgado F, Albornoz L, Cortéz C, Stashenko E, Urrea-Vallejo K, Nagles E, Galicia-Virviescas C, Cornejo A, Ardiles A, Simirgiotis M, et al. Secondary metabolite profiling of species of the genus Usnea by UHPLC-ESI-OT-MS-MS. Molecules. 2017; 23(1):54. 10.3390/molecules23010054 29280946
17 Jin J, Rao Y, Bian X, Zeng A, Yang G. Solubility of (+)-usnic acid in water, ethanol, acetone, ethyl acetate and n-hexane. J Solution Chem. 2013; 42(5):1018–1027. 10.1007/s10953-013-0010-1
18 Index M. Monograph number 09893: Usnic acid In: O'Neil MJ, Heckelman PE, Koch CB, Roman KJ, editors. The Merck Index an Encylopedia of Chemicals, Drugs and Biologicals. Fourteenth ed. Whitehouse Station, NJ: Merck Research Laboratories; 2006.
19 Ranković B, Kosanić M. Lichen Secondary Metabolites: Bioactive Properties and Pharmaceutical Potential. Cham, Switzerland: Springer International Publishing; 2015. Lichens as a potential source of bioactive secondary metabolites; p. 1–26. 10.1007/978-3-319-13374-4_1
20 Cocchietto M, Skert N, Nimis PL, Sava G. A review on usnic acid, an interesting natural compound. Naturwissenschaften. 2002; 89(4):137–146. 10.1007/s00114-002-0305-3 12061397
21 Sharma RK, Jannke PJ. Acidity of usnic acid. Indian J Chem. 1966; 4(1):16–18.
22 Backor M, Gaburjáková J, Hudák J, Ziegler W. The biological role of secondary metabolites from lichens. 1. The influence of usnic acid on bimolecular lipid membranes. Physiol Plant. 1997;29:67–71.
23 Cardarelli M, Serino G, Campanella L, Ercole P, De Cicco Nardone F, Alesiani O, Rossiello F. Antimitotic effects of usnic acid on different biological systems. Cell Mol Life Sci. 1997; 53(8):667–672. 10.1007/s000180050086 9351470
24 Guo L, Shi Q, Fang JL, Mei N, Ali AA, Lewis SM, Leakey JE, Frankos VH. Review of usnic acid and Usnea barbata toxicity. J Environ Sci Health Part C Environ Carcinog Ecotoxicol Rev. 2008; 26(4):317–338. 10.1080/10590500802533392 19034791
25 Abo-Khatwa AN, al-Robai AA, al-Jawhari DA. Lichen acids as uncouplers of oxidative phosphorylation of mouse-liver mitochondria. Nat Toxins. 1996; 4(2):96–102. 10.1002/19960402NT7 8726330
26 Han D, Matsumaru K, Rettori D, Kaplowitz N. Usnic acid-induced necrosis of cultured mouse hepatocytes: Inhibition of mitochondrial function and oxidative stress. Biochem Pharmacol. 2004; 67(3):439–451. 10.1016/j.bcp.2003.09.032 15037196
27 Pramyothin P, Janthasoot W, Pongnimitprasert N, Phrukudom S, Ruangrungsi N. Hepatotoxic effect of (+)usnic acid from Usnea siamensis Wainio in rats, isolated rat hepatocytes and isolated rat liver mitochondria. J Ethnopharmacol. 2004; 90(2-3):381–387. 10.1016/j.jep.2003.10.019 15013205
28 Shibamoto T, Wei CI. Mutagenicity of lichen constituents. Environ Mutagen. 1984; 6(5):757–762. 10.1002/em.2860060512 6236972
29 Cansaran D, Kahya D, Yurdakulola E, Atakol O. Identification and quantitation of usnic acid from the lichen Usnea species of Anatolia and antimicrobial activity. Z Naturforsch C J Biosci. 2006; 61(11-12):773–776. 10.1515/znc-2006-11-1202 17294685
30 Frankos VH. NTP nomination for usnic acid and usnea barbata herb. College Park, MD: Food and Drug Administration, Division of Dietary Supplement Programs; 2005. https://ntp.niehs.nih.gov/ntp/htdocs/chem_background/exsumpdf/usnicacid_508.pdf.
31 Malhotra S, Subban R, Singh AP. Lichens- role in traditional medicine an drug discovery. Internet J Alt Med. 2007; 5(2):1–6.
32 Chaowuttikul C, Thitikornpong W, Palanuvej C, Ruangrungsi N. Quantitative determination of usnic acid content in Usnea siamensis by TLC-densitometry and TLC image analysis. Res J Pharm Biol Chem Sci. 2014; 5(1):118–125.
33 Esslinger TL. A cumulative checklist for the lichen-forming, lichenicolous and allied fungi of the continental United States and Canada. North Dakota State University; 2007. https://www.ndsu.edu/instruct/esslinge/chcklst/chcklst7.htm
34 Buhner SH. Herbal antibiotics: Natural alternatives for treating drug-resistant bacteria. North Adams, MA: Storey Publishing; 2012.
35 Rahman M, Falck-Ytter AB, Antonsen ØG, Strætkvern KO. Reindeer lichen (Cladonia stellaris) from a Norwegian mountain region as a sustainable source of usnic acid. Int J Appl Res Nat Prod. 2015; 8(3):17–23.
36 Doell J. The saga of Usnea longissima in California. Bull California Lichen Soc. 2004; 11(2):37–44.
37 Safak B, Ciftci IH, Ozdemir M, Kiyildi N, Cetinkaya Z, Aktepe OC, Altindis M, Asik G. In vitro anti-Helicobacter pylori activity of usnic acid. Phytother Res. 2009; 23(7):955–957. 10.1002/ptr.2690 19367654
38 Bazarnova Y, Politaeva N, Lyskova N. Research for the lichen Usnea barbata metabolites. Z Naturforsch C J Biosci. 2018; 73(7-8):291–296. 10.1515/znc-2017-0177 29596056
39 Honda NK, Pavan FR, Coelho RG, de Andrade Leite SR, Micheletti AC, Lopes TI, Misutsu MY, Beatriz A, Brum RL, Leite CQ. Antimycobacterial activity of lichen substances. Phytomedicine. 2010; 17(5):328–332. 10.1016/j.phymed.2009.07.018 19683421
40 Lucarini R, Tozatti M, De A, Salloum O, Crotti AE, Silva M, Gimenez V, Groppo M, Januario AH, Martins CH, et al. Antimycobacterial activity of Usnea steineri and its major constituent (+)-usnic acid. Afr J Biotechnol. 2012; 11(20):4636–4639.
41 Tozatti MG, Ferreira DS, Flauzino LG, Moraes Tda S, Martins CH, Groppo M, Andrade e Silva ML, Januário AH, Pauletti PM, Cunhaa WR. Activity of the lichen Usnea steineri and its major metabolites against gram-positive, multidrug-resistant bacteria. Nat Prod Commun. 2016; 11(4):493–496. 10.1177/1934578X1601100419 27396202
42 Rukayadi Y, Shim JS, Hwang JK. Screening of Thai medicinal plants for anticandidal activity. Mycoses. 2008; 51(4):308–312. 10.1111/j.1439-0507.2008.01497.x 18331446
43 Tay T, Türk AO, Yilmaz M, Türk H, Kivanç M. Evaluation of the antimicrobial activity of the acetone extract of the lichen Ramalina farinacea and its (+)-usnic acid, norstictic acid, and protocetraric acid constituents. Z Naturforsch C J Biosci. 2004; 59(5-6):384–388. 10.1515/znc-2004-5-617 18998406
44 Mahadik ND, Morey MV, Behera BC. Cardiovascular-protective, antioxidative, and antimicrobial properties of natural thallus of lichen Usnea complanata. Lat Am J Pharm. 2011; 30(2):220–228.
45 Yamamoto Y, Miura Y, Kinoshita Y, Higuchi M, Yamada Y, Murakami A, Ohigashi H, Koshimizu K. Screening of tissue cultures and thalli of lichens and some of their active constituents for inhibition of tumor promoter-induced Epstein-Barr virus activation. Chem Pharm Bull (Tokyo). 1995; 43(8):1388–1390. 10.1248/cpb.43.1388 7553984
46 Ebrahim HY, Elsayed HE, Mohyeldin MM, Akl MR, Bhattacharjee J, Egbert S, El Sayed KA. Norstictic acid inhibits breast cancer cell proliferation, migration, invasion, and in vivo invasive growth through targeting c-met. Phytother Res. 2016; 30(4):557–566. 10.1002/ptr.5551 26744260
47 Takai M, Uehara Y, Beisler JA. Usnic acid derivatives as potential antineoplastic agents. J Med Chem. 1979; 22(11):1380–1384. 10.1021/jm00197a019 160461
48 Kristmundsdóttir T, Aradóttir HA, Ingólfsdóttir K, Ogmundsdóttir HM. Solubilization of the lichen metabolite (+)-usnic acid for testing in tissue culture. J Pharm Pharmacol. 2002; 54(11):1447–1452. 10.1211/002235702225 12495546
49 Kumar KC, Müller K. Lichen metabolites. 2. Antiproliferative and cytotoxic activity of gyrophoric, usnic, and diffractaic acid on human keratinocyte growth. J Nat Prod. 1999; 62(6):821–823. 10.1021/np980378z 10395495
50 Choudhary MI, Azizuddin SJ. Atta ur R. Bioactive phenolic compounds from a medicinal lichen, Usnea longissima. Phytochemistry. 2005; 66(19):2346–2350. 10.1016/j.phytochem.2005.06.023 16102789
51 Azizuddin IS, Choudhary MI. In vivo anti-inflammatory and anti-platelet aggregation activities of longissiminone A, isolated from Usnea longissima. Pak J Pharm Sci. 2017; 30(4):1213–1217. 29039316
52 Okuyama E, Umeyama K, Yamazaki M, Kinoshita Y, Yamamoto Y. Usnic acid and diffractaic acid as analgesic and antipyretic components of Usnea diffracta. Planta Med. 1995; 61(2):113–115. 10.1055/s-2006-958027 7753915
53 Engel K, Schmidt U, Reuter J, Weckesser S, Simon-Haarhaus B, Schempp CM. Usnea barbata extract prevents ultraviolet-B induced prostaglandin E2 synthesis and COX-2 expression in HaCaT keratinocytes. J Photochem Photobiol B. 2007; 89(1):9–14. 10.1016/j.jphotobiol.2007.08.002 17766140
54 Krishna DR, Venkataramana D. Pharmacokinetics of D(+)-usnic acid in rabbits after intravenous and oral administration. Drug Metab Dispos. 1992; 20(6):909–911. 1362945
55 Krishna DR, Ramana DV, Mamidi NV. In vitro protein binding and tissue distribution of D(+) usnic acid. Drug Metabol Drug Interact. 1995; 12(1):53–63. 10.1515/DMDI.1995.12.1.53 7555002
56 Dobrescu D, Tănăsescu M, Mezdrea A, Ivan C, Ordosch E, Neagoe F, Rizeanu A, Trifu L, Enescu V. Contributions to the complex study of some lichens-Usnea genus. Pharmacological studies on Usnea barbata and Usnea hirta species. Rom J Physiol. 1993; 30(1-2):101–107. 7982010
57 Zhu J, Zhang X, Chen X, Sun Y, Dai Y, Chen C, Zhang T, Yan Z. Studies on the regulation of lipid metabolism and the mechanism of the aqueous and ethanol extracts of Usnea. Biomed Pharmacother. 2017;94:930–936. 10.1016/j.biopha.2017.08.012 28810520
58 Marshak A, Kuschner M. The action of streptomycin and usnic acid on the development of tuberculosis in guinea pigs. Public Health Rep. 1950; 65(5):131–144. 10.2307/4587227 15405524
59 da Silva Santos NP, Nascimento SC, Wanderley MS, Pontes-Filho NT, da Silva JF, de Castro CM, Pereira EC, da Silva NH, Honda NK, Santos-Magalhães NS. Nanoencapsulation of usnic acid: An attempt to improve antitumour activity and reduce hepatotoxicity. Eur J Pharm Biopharm. 2006; 64(2):154–160. 10.1016/j.ejpb.2006.05.018 16899355
60 Ribeiro-Costa RM, Alves AJ, Santos NP, Nascimento SC, Gonçalves EC, Silva NH, Honda NK, Santos-Magalhães NS. In vitro and in vivo properties of usnic acid encapsulated into PLGA-microspheres. J Microencapsul. 2004; 21(4):371–384. 10.1080/02652040410001673919 15513745
61 Odabasoglu F, Cakir A, Suleyman H, Aslan A, Bayir Y, Halici M, Kazaz C. Gastroprotective and antioxidant effects of usnic acid on indomethacin-induced gastric ulcer in rats. J Ethnopharmacol. 2006; 103(1):59–65. 10.1016/j.jep.2005.06.043 16169175
62 Dailey RN, Montgomery DL, Ingram JT, Siemion R, Vasquez M, Raisbeck MF. Toxicity of the lichen secondary metabolite (+)-usnic acid in domestic sheep. Vet Pathol. 2008; 45(1):19–25. 10.1354/vp.45-1-19 18192570
63 Aalto-Korte K, Lauerma A, Alanko K. Occupational allergic contact dermatitis from lichens in present-day Finland. Contact Dermat. 2005; 52(1):36–38. 10.1111/j.0105-1873.2005.00495.x 15701128
64 Mitchell JC. Allergy to lichens. Allergic contact dermatitis from usnic acid produced by lichenized fungi. Arch Dermatol. 1965; 92(2):142–146. 10.1001/archderm.1965.01600140030006 11850913
65 Rafanelli S, Bacchilega R, Stanganelli I, Rafanelli A. Contact dermatitis from usnic acid in vaginal ovules. Contact Dermat. 1995; 33(4):271–272. 10.1111/j.1600-0536.1995.tb00484.x 8654084
66 Sheu M, Simpson EL, Law SV, Storrs FJ. Allergic contact dermatitis from a natural deodorant: A report of 4 cases associated with lichen acid mix allergy. J Am Acad Dermatol. 2006; 55(2):332–337. 10.1016/j.jaad.2004.12.043 16844524
67 Favreau JT, Ryu ML, Braunstein G, Orshansky G, Park SS, Coody GL, Love LA, Fong TL. Severe hepatotoxicity associated with the dietary supplement LipoKinetix. Ann Intern Med. 2002; 136(8):590–595. 10.7326/0003-4819-136-8-200204160-00008 11955027
68 Neff GW, Reddy KR, Durazo FA, Meyer D, Marrero R, Kaplowitz N. Severe hepatotoxicity associated with the use of weight loss diet supplements containing ma huang or usnic acid. J Hepatol. 2004; 41(6):1062–1064. 10.1016/j.jhep.2004.06.028 15582145
69 Sanchez W, Maple JT, Burgart LJ, Kamath PS. Severe hepatotoxicity associated with use of a dietary supplement containing usnic acid. Mayo Clin Proc. 2006; 81(4):541–544. 10.4065/81.4.541 16610575
70 Durazo FA, Lassman C, Han SH, Saab S, Lee NP, Kawano M, Saggi B, Gordon S, Farmer DG, Yersiz H, et al. Fulminant liver failure due to usnic acid for weight loss. Am J Gastroenterol. 2004; 99(5):950–952. 10.1111/j.1572-0241.2004.04165.x 15128366
71 Anonymous. FDA warns against dietary supplement. OBGYN NET; 2001. https://web.archive.org/web/20041119151559/http://www.obgyn.net/newsrx/general_health-Nutriceuticals-20011217-11.asp
72 Koparal AT, Tüylü BA, Türk H. In vitro cytotoxic activities of (+)-usnic acid and (-)-usnic acid on V79, A549, and human lymphocyte cells and their non-genotoxicity on human lymphocytes. Nat Prod Res. 2006; 20(14):1300–1307. 10.1080/14786410601101910 17393655
73 al-Bekairi AM, Qureshi S, Chaudhry MA, Krishna DR, Shah AH. Mitodepressive, clastogenic and biochemical effects of (+)-usnic acid in mice. J Ethnopharmacol. 1991; 33(3):217–220. 10.1016/0378-8741(91)90079-S 1833591
74 Center for Food Safety and Applied Nutrition (CFSAN). FDA warns consumers not to use the dietary supplement LipoKenetix. Food and Drug Administration, Center for Food Safety and Applied Nutrition; 2001. http://www.cfsan.fda.gov/~dms/ds-lipo.html [Accessed: July 10, 2012]
75 Center for Food Safety and Applied Nutrition (CFSAN). Letter to distributor of hazardous dietary supplement, LipoKenetix. Food and Drug Administration, Center for Food Safety and Applied Nutrition; 2001. http://www.cfsan.fda.gov/~dms/ds-ltr26.html [Accessed: July 10, 2012]
76 National Toxicology Program (NTP). NTP technical report on the toxicity studies of (+)-usnic acid (CASRN 7562-61-0) administered in feed to F344/N Nctr rats and B6C3F1/Nctr mice. Research Triangle Park: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2021. NTP Toxicity Report No. 104 (in progress).
77 McCune B, Geiser L, Sharnoff SD, Sharnoff S, Mikulin AG. Macrolichens of the Pacific Northwest. Corvallis, OR: Oregon State University Press; 1997.
78 National Toxicology Program (NTP). Specifications for the conduct of studies to evaluate the toxic and carcinogenic potential of chemical, biological and physical agents in laboratory animals for the National Toxicology Program (NTP). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2006.
79 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
80 Kaplan EL, Meier P. Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958; 53(282):457–481. 10.1080/01621459.1958.10501452
81 Cox DR. Regression models and life-tables. J R Stat Soc B. 1972; 34(2):187–202. 10.1111/j.2517-6161.1972.tb00899.x
82 Tarone RE. Tests for trend in life table analysis. Biometrika. 1975; 62(3):679–690. 10.1093/biomet/62.3.679
83 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
84 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
85 Armitage P. Tests for linear trends in proportions and frequencies. Biometrics. 1955; 11(3):375–386. 10.2307/3001775
86 Skouteris GG, McMenamin M. Transforming growth factor-alpha-induced DNA synthesis and c-myc expression in primary rat hepatocyte cultures is modulated by indomethacin. Biochem J. 1992; 281(Part 3):729–733. 10.1042/bj2810729 1531590
87 Fisher RA. On the interpretation of X2 from contingency tables, and the calculation of P. J R Stat Soc. 1922; 85(1):87–94. 10.2307/2340521
88 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
89 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1/2):133–145. 10.2307/2333011
90 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
91 Girard DM, Sager DB. The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987; 43(1):225–234. 10.2307/2531963 3567307
92 Stefl B, Janovská A, Hodný Z, Rossmeisl M, Horáková M, Syrový I, Bémová J, Bendlová B, Kopecký J. Brown fat is essential for cold-induced thermogenesis but not for obesity resistance in aP2-Ucp mice. Am J Physiol. 1998; 274(3):E527–E533. 10.1152/ajpendo.1998.274.3.E527 9530137
93 Korde AS, Sullivan PG, Maragos WF. The uncoupling agent 2,4-dinitrophenol improves mitochondrial homeostasis following striatal quinolinic acid injections. J Neurotrauma. 2005; 22(10):1142–1149. 10.1089/neu.2005.22.1142 16238490
94 National Toxicology Program (NTP). Genotoxicity test of usnic acid in Salmonella. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2006. https://manticore.niehs.nih.gov/datasets/search/trf?casrn=125-46-2 [Accessed: December 9, 2018]
95 Dertinger SD, Bishop ME, McNamee JP, Hayashi M, Suzuki T, Asano N, Nakajima M, Saito J, Moore M, Torous DK, et al. Flow cytometric analysis of micronuclei in peripheral blood reticulocytes: I. Intra- and interlaboratory comparison with microscopic scoring. Toxicol Sci. 2006; 94(1):83–91. 10.1093/toxsci/kfl075 16888078
96 Dertinger SD, Torous DK, Tometsko KR. Simple and reliable enumeration of micronucleated reticulocytes with a single-laser flow cytometer. Mutat Res. 1996; 371(3-4):283–292. 10.1016/S0165-1218(96)90117-2 9008730
97 Roach JA, Musser SM, Morehouse K, Woo JY. Determination of usnic acid in lichen toxic to elk by liquid chromatography with ultraviolet and tandem mass spectrometry detection. J Agric Food Chem. 2006; 54(7):2484–2490. 10.1021/jf052767m 16569032