# Discussion

The selection of exposure levels of (+/−)-usnic acid in Usnea lichens for F344/N Nctr rats and B6C3F1/Nctr mice was based on a 2-week range-finding study conducted prior to this 3-month study (Appendix J) during which feed concentrations of 1,250 ppm in rats and 600 and 1,200 ppm in mice caused rapid weight loss and some morbidity. The selected exposure levels corresponded to target doses of 2, 5, 10, 30, and 100 mg (+/−)-usnic acid/kg body weight/day (mg/kg/day) for rats and 5, 10, 30, 100, and 200 mg/kg/day for mice, calculated from historical feed consumption and body weight data from the relevant strains. The observed daily doses calculated from the study data correlated closely for the rats but were higher than the target dose in mice (Appendix F).

This 3-month feed study has demonstrated that exposure to ground Usnea lichens containing 720 ppm (60 mg/kg/day) (+/−)-usnic acid can be toxic to male and female F344/N Nctr rats, as evidenced by significant weight loss, morbidity, or death after 4 weeks of exposure. Because other (unknown) potentially toxic lichen secondary metabolites were also present at low concentrations in the ground Usnea lichens preparation used in these studies, it is not possible to attribute all the observed toxicity to (+/−)-usnic acid. However, since the Usnea lichens preparation was standardized on (+/−)-usnic acid content, ppm (+/−)-usnic acid was used to define exposure levels as this was useful for comparison to the comparative studies using pure (+)-usnic acid in NTP TOX 104.^76^ Increased incidence of hepatocellular degeneration was observed in male rats exposed to 120, 360, and 720 ppm (+/−)-usnic acid in Usnea lichens, and in females exposed to 720 ppm. Three-month exposure to Usnea lichens was less toxic to B6C3F1/Nctr mice; all males and 9/10 females in the 360 ppm (60 mg/kg/day) exposure group survived to the end of the study with no overt signs of morbidity and relatively small decreases in body weight. However, increased incidence of hepatocellular degeneration was observed in both male and female mice exposed to 360 ppm (+/−)-usnic acid in Usnea lichens; in females, atrophy of the ovary was observed in both the 180 and 360 ppm exposure groups. Prolonged estrous cycle length and estrus stage were also observed in female mice exposed to 360 ppm (+/−)-usnic acid, but not at lower exposure levels. In both rats and mice, a no-observed-adverse-effect level (NOAEL) of 60 ppm was observed. For the F344/N Nctr rats, 60 ppm is equivalent to target and observed doses of approximately 5 mg/kg/day, or 150–200 mg Usnea lichens powder/kg/day. For the B6C3F1/Nctr mice, 60 ppm is equivalent to target and observed doses of approximately 10 and 15–20 mg, respectively, of (+/−)-usnic acid/kg/day; or observed doses of approximately 500–700 mg Usnea lichens powder/kg/day. The recommended dose of Usnea lichens in herbal medicine is 6–9 g per day corresponding to 120–180 mg/kg/day for a patient weighing 50 kg. The use of (+)-usnic acid derived from lichens as a weight-loss agent has been associated with severe hepatotoxicity in humans.^24,30^ It is noteworthy that in both rats and mice, 3-month exposure to (+/−)-usnic acid from Usnea lichens resulted in both significant weight loss and hepatotoxicity.

Usnea lichens were also observed to be less toxic in B6C3F1/Nctr mice than in F344/N Nctr rats in the 2-week acute toxicity studies reported in Appendix J. In these studies, hepatic adenosine 5’-triphosphate (ATP) levels were also measured as a biomarker for (+/−)-usnic acid’s membrane uncoupling activity.^24^ Significant hepatic ATP depletion was observed at lower exposure concentrations than those that produced hepatotoxicity, and lower exposures (as mg/kg/day) were required to decrease ATP levels in the rats than were required in the mice. Mice express high levels of mitochondrial uncoupling proteins such as UCP-1 in their tissues to generate heat for thermoregulation.^92^ Both UCP-1 and (+)-usnic acid uncouple mitochondrial ATP synthesis by facilitating proton diffusion across the inner mitochondrial membrane, which produces heat rather than ATP.^24,25,93^ It is probable, therefore, that mice have a greater capacity than larger animals to compensate for the uncoupling effects of (+/−)-usnic acid by downregulating UCP-1 expression.

Usnea lichens appear to be significantly more toxic than equivalent concentrations of pure (+)-usnic acid that were used in the companion 3-month toxicity study of (+)-usnic acid in feed.^76^ For example, exposure to 720 ppm pure (+)-usnic acid had no effect on survival; all rats exposed to 720 ppm (+)-usnic acid survived until the end of the 3-month exposure. Male and female mice exposed to Usnea lichens containing 360 ppm (+/−)-usnic acid exhibited significant hepatotoxicity, whereas no hepatotoxicity was observed in mice exposed to 360 ppm pure (+)-usnic acid. This increase in toxicity is unlikely to be due to the presence of (−)-usnic acid in Usnea lichens because it contributed to <3% of the total (+/−)-usnic acid in the lichens. Significant concentrations of other potentially toxic secondary metabolites, such as salazinic acid, have been reported to be present in both U. cavernosa and U. scabrata^3^ and at least eight unknown metabolite peaks were resolved by HPLC of a methanol extract of the Usnea lichen test material used in this study (Appendix H). Identification of these unknown secondary metabolites was beyond the scope and focus of the study. However, it is now well established that different Usnea (20 species) contain different combinations of secondary metabolites,^14,16^ which suggests that the potential toxicity of herbal preparations of Usnea lichens will vary according to which Usnea species they are derived from.

The toxicokinetic studies (Appendix K) demonstrated that in rats, and to a lesser extent in mice, exposure to Usnea lichens containing (+/−)-usnic acid resulted in greater concentrations of usnic acid in liver (rats only) and serum than did equivalent doses of pure (+)-usnic acid. This observation was not due to differences in feed consumption, which was similar between animals fed Usnea lichens and those fed equivalent amounts of pure (+)-usnic acid (Appendix F). Thus, it is possible that components in the lichens increase their toxicity by altering the disposition, metabolism, or clearance of (+/−)-usnic acid in addition to being directly toxic themselves. Usnea lichens were also observed to be more toxic than pure (+)-usnic acid when administered at higher exposure levels for 14 days (Appendix J of NTP TOX 104^76^) and taken together these 14-day and 90-day studies demonstrate that the toxicity of individual Usnea lichen preparations cannot be directly predicted from the toxicity of pure (+)-usnic acid.

Exposure of F344/N Nctr rats to Usnea lichens containing (+/−)-usnic acid in feed for 3 months resulted in severe toxicity and morbidity at exposure levels equivalent to 720 ppm of (+/−)-usnic acid. Significant hepatotoxicity was observed in male rats exposed to 120, 360, and 720 ppm, and in female rats exposed to 720 ppm. Exposure of B6C3F1/Nctr mice to Usnea lichens containing (+/−)-usnic acid in feed for 3 months resulted in hepatotoxicity at an exposure level equivalent to 360 ppm (+/−)-usnic acid in both male and female mice, and in ovarian atrophy and extended estrous cycle length in females exposed to 180 and 360 ppm. The estrus stage was extended in both mice and rats at 360 ppm. Body weight was significantly reduced compared to vehicle control values at exposure levels of 360 and 720 ppm in rats and of 360 ppm in mice. Male and female B6C3F1/Nctr mice exposed to 600 ppm (+/−)-usnic acid for 2 weeks exhibited increased frequencies of erythrocyte micronuclei. A NOAEL of 60 ppm of (+/−)-usnic acid in Usnea lichens administered in the feed was established for both F344/N Nctr rats and B6C3F1/Nctr mice based on the results of these subchronic studies.